# INTRODUCTION

Suicide remains a critical public health concern, with suicide rates increasing by 33% in the United States (US) between 1999 and 2019. Suicide rates vary by sex, race, age, and occupation, including military service, the latter of which is independently associated with increased risk for suicide. The suicide rate among US Veterans is 1.5 times that of the general population, when adjusted for age and sex.^1^ While Veterans comprise only 8% of the US population, 13.8% (6,435) of all suicides in 2018 occurred in Veterans.^1^ Similar to the general population, male sex, non-Hispanic white race, mental health diagnoses, and age (55-74), are risk factors in Veterans. Therefore, suicide prevention is the highest priority for the US Department of Veterans Affairs (VA).^2^

The National Strategy for Preventing Veteran Suicide 2018–2028^2^ has outlined several goals, including increased surveillance and research to identify at-risk individuals and evaluate additional potential risk and protective factors. As further outlined in the 2020 National Veteran Suicide Annual Report, Veterans and active military “do not live, work, and serve in isolation….”,^1^ recognizing that risk and protective factors are not confined solely to the individual. Therefore, evaluating these factors through the lens of a socioecological framework can provide context for developing suicide prevention policies and practices.

The Centers for Disease Control and Prevention (CDC) suggests that prevention efforts for any health or disease issue require an understanding of the underlying factors that influence the issue. The CDC’s Social-Ecological Model (SEM) (Figure 1) is a 4-tiered framework for organizing risk and protective factors, which may then inform prevention strategies.^3^ The 4 strata, from macro to micro level are: Societal (factors concerning large-scale issues such as social and cultural norms, and guiding rules such as policies or laws); Community (factors limited to a certain region like a neighborhood, school, or workplace); Relational (factors involved with direct person-to-person interaction); Individual (person characteristics such as demographics, health, and beliefs). The overlapping rings of the SEM illustrate how factors at each level (individual, relationship, community, and society) impact factors at other levels; as do the various risk and protective factors associated with suicide. Table 1 provides a list of examples as to how different factors could be categorized within the model. Depending on how they are operationalized, some factors could conceptually fit into multiple categories.

Figure 1 Social-Ecological Model^*^ * https://www.cdc.gov/violenceprevention/publichealthissue/social-ecologicalmodel.html

Table 1 Examples of Risk Factors for Each Domain within the Social-Ecological Model^a^

Individual | Relationship
- Previous suicide attempt; - Mental illness, such as depression; - Gender; - Criminal problems; - Financial strain; - Impulsive or aggressive tendencies; - Job problems/unemployment; - Legal problems; - Serious illness; - Substance use disorder | - Adverse childhood experiences such as child abuse and neglect; - Bullying; - Family history of suicide; - Relationship problems such as a break-up, violence, or loss; - Sexual violence
Community | Societal
- Barriers to health care; - Cultural and religious beliefs, such as a belief that suicide is a noble resolution of a personal problem; - Suicide cluster in a community | - Economic downturn/depression; - Seasonal variation; - Stigma associated with mental illness or help-seeking; - Easy access to lethal means, such as firearms or medications; - Unsafe media portrayals of suicide

a Examples were derived from the CDC^3^ and a systematic review done by Cramer et al^5^

This is the second of a 2-part review nominated by VA Health Services Research and Development (HSR&D). The first review focused on community-based interventions for suicide prevention.^39^ This second review focuses on research conducted since 2011 that reported risk and protective factors related to suicide or suicide attempt in Veteran or active duty military populations. The topic was nominated by VA HSR&D to further develop research priorities and identify areas for future funding on suicide prevention in VA. In collaboration with VA leadership and members of a Technical Expert Panel (TEP) the following Key Question was developed: What are the risk and protective factors for suicidal behaviors (attempts or death by suicide) across social-ecological levels of risk?

To answer this question, we provide an evidence map of identified risk and protective factors for suicidal behaviors in populations not known to be at high risk (eg, populations limited to those with mental health disorders or known prior suicide attempts). Evidence maps involve a systematic search of a broad field to identify gaps in knowledge and/or future research needs and presents results in a user-friendly format, often a visual figure or graph, or a searchable database.^40^ Evidence maps are useful when there is both abundance and diversity of research. Their main utility is for displaying areas where research is concentrated and gaps that need to be addressed. Using the CDC Social-Ecological Model,^3^ we categorized the reported risk and protective factors into 1 of 4 domains: Individual, Relational, Community, or Societal. We summarize studies by categories within this framework without commenting on the results or findings of individual studies.