# APPENDIX D EVIDENCE TABLE

Appendix Table D1 Study Characteristics and Outcomes for All Low and Moderate Risk of Bias Studies (k=54)

Appendix Table D2 Study Characteristics and Outcomes Related to Military Occupation as a Risk Factor Among Low and Moderate Risk of Bias Studies (k=7)

Appendix Table D3 Study Characteristics and Outcomes Related to Deployment Status Among Low and Moderate Risk of Bias Studies (k=14)