# APPENDIX C PEER REVIEW COMMENTS/AUTHOR RESPONSES

Question Text | Reviewer Number | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 2 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 5 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 6 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 7 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 8 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 9 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 1 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 2 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 3 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 4 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 5 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 6 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 7 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 8 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 9 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 1 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 2 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 3 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 4 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 5 | Yes - Two articles available here: https://onlinelibrary.wiley.com/doi/abs/10.1111/sltb.12511 and https://www.sciencedirect.com/science/article/abs/pii/S0165032718327757?via%3Dihub | Monteith et al. was excluded from this review as it was conducted in a sub-population; included studies had to investigate risk factors within a general Veteran/armed forces population. Barnes et at. was excluded at abstract level as developing predictive models was outside of the scope of this review.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 6 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 7 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 8 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 9 | Yes - Montgomery, A. E., Dichter, M. E., Byrne, T. H., & Blosnich, J. R. (2021). Intervention to address homelessness and all-cause and suicide mortality among unstably housed U.S. Veterans, 2012–2016. Journal of Epidemiology and Community Health, 75, 380–386. doi:10.1136/jech-2020-214664 | Montgomery et al. was excluded as intervention studies were explicitly excluded from this review.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 9 | Montgomery, A. E., Dichter, M. E., & Blosnich, J. R. (2021). Gender differences in the predictors of suicide-related morbidity among Veterans reporting current housing instability. Medical Care, 59, S36–S41. doi:10.1097/MLR.0000000000001422 33438881 | Montgomery et al. was excluded from this review as it was conducted in a sub-population; included studies had to investigate risk factors within a general Veteran/armed forces population.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 9 | Cusack, M. C., Montgomery, A. E., Cashy, J., Dichter, M. E., Byrne, T. H., & Blosnich, J. R. Examining Veteran housing instability and mortality by homicide, suicide, and unintentional injury. (2020). Journal of Social Distress and Homelessness, online ahead of print. doi:10.1080/10530789.2020.1801020 | Thank you, the Cusack et at. was not identified by our search and we have included this article and updated our report to reflect this.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Under the individual section a rich data resource from VA is described. - this is an important note to consider how much information is available | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | APA shows Posttraumatic stress disorder (PTSD) as the way it is presented (no hyphen, not 2 words) | We have updated all instances of this throughout the report to remove the hyphen.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | p4, line 36-37, mentioned diverse categorization of deployment status - since this seems foundational information, is it a PI generated issue in what information was collected or another issue in terms of not having common data elements, etc.? | Many authors defined their deployment variables differently, ie, some used currently vs. previously deployed, while others used ever vs. never and some broke this down further by number of deployments. We have added information into the report for clarity.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | At the individual level a description of the studies were presented but not for the other levels. this could be a bolstered description to help from level to level, e.g., retrospective data analysis based upon VHA records, vs original prospective data collection, etc. | We’ve reorganized our report slightly to include these more detailed descriptions in the corresponding sections (ie, low risk of bias or prospective studies).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | ???what is it we can conclude about PTSD and suicide??? | The following sentence was added to the report: Post-traumatic stress disorder (PTSD) was consistently shown to be a risk factor for suicide attempts but results were inconsistent for suicide.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | I am unsure the order of presentation of tables and figures - not alphabetical and not by frequency - mentioning it for considering the best way to present the list of factors on the Y axes. | We thank the author for the suggestion, we grouped factors by socioecological model domains, and within those domains we tried to group like factors near each other. We initially thought we might subcategorize, but there was no foundational framework to do so.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | page line 40 - change to “…than 100,000 individuals, 10 studies enrolled Veterans….” | Thank you, this has been corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | on page 13, line 50; I feel the description of ROB needs more; is there a way to provide any kind of examples in the text (and some in the Executive Summary, too)? It is not clear to me how all of these prognostic factors might indicate bias in a study of suicide prevention. What kind of bias was found within the research that was screened? Knowing that may help inform investigators and improve our new research studies moving forward. page 18, line 27: this sentence was hard to read, could some commas be added? “Other factors at the individual, community or relational level while sometimes found to be associated with suicide and attempts were reported in only 1 or 2 studies thus limiting conclusions.” | The prognostic factors themselves do not create bias, it’s the methodological decisions made by the authors that may introduce bias into a study. We discuss limitations of study quality in the Limitations section. We also have discussed the issues of risk of bias in our future research needs section: “More refined analytic methods to adjust for known and potential confounders is important and a better understanding of whether results are due to exploratory analyses, chance, or limited statistical power. Additional work is needed to validate and harmonize how factors and confounders are operationalized, measured, and reported as well as the analytic models used.”; This sentence has been edited to for clarity. “Community-level, relational-level, and other individual-level factors were reported in only 1 or 2 studies. These factors were sometimes associated with suicide and attempts, but the few studies limited confidence. Thus, further exploration of factors such as firearm status, marital status, and various forms of interpersonal violence is warranted.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 2 says studies of “nontraditional” risk or protective factors were included, which doesn’t align with Table 2 of inclusion/exclusion criteria. These should be aligned, and if the inclusion criteria of “studies of ‘nontraditional’ risk or protective factors” is retained, it should be clarified/specified. | We’ve changed the term “nontraditional” to “modifiable”. Due to the large amounts of research available on sex, race and age as risk factors for suicidal behaviors, we focused our report on other factors that have the potential to be modified, to align with VAs mission to reduce suicidal behaviors.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Homelessness is not a community level factor. Individual experience of homelessness (i.e., being homeless) is an individual-level factor. If the studies included were indeed evaluating the degree of homelessness in the community as an exposure variable, then this should be specified as such. If they were assessing the association between being homeless and suicide risk, then these studies should be re-categorized into the individual level group. | We agree with the reviewer and have moved homelessness to the individual domain.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | It seems overly simplistic to state that the converse of a risk factor could be interpreted as a protective factor (page 8). Protective factors should ideally operate as a buffer – reducing risk despite/in the context of harmful experiences. Recommend removing this statement. | We agree and have removed this statement.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | When the data source is specified as “VHA” and “DoD” are these all administrative data? It would be good to specify this so that people know it is admin data vs. simply the study took place at VHA. Specifically Table 3 could say “VHA administrative databases” or similar. | Thank you, we’ve added to Table 3 to clarify that this refers to VHA or DoD administrative data.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | There is some discussion related to standardization of risk factors/modeling adjustments - am wondering if it is worthwhile to mention efforts made by NIH and other mechanisms that fund suicide prevention research to use common data elements (including measure of risk factors) to increase comparability across studies | We agree. While not specifically mentioning efforts by NIH we note that future research would benefit from common data elements including measures of risk factors.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | This report is excellent. Some minor comments are noted below. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | Excluding studies of populations known to be at high risk by virtue of mental health diagnoses or past suicide attempts likely limits the implications regarding risk and protective factors for those at heightened chronic suicide risk. This may be important to note outright. | We agree that it limits broader implications, the intent was to review risk factors in broad populations, not to look at groups that were otherwise known to be at high-risk. Our goal was to see, in general populations, what risk factors were identified. Language has been added to the report in an attempt to make this more clear.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | More description of the operationalization used to define “nontraditional” risk or protective factors and the rationale for excluding these from the review would be useful to include. Also, demographics were listed in Table 4, but weren’t these excluded due to being “nontraditional”? | We’ve changed the term “nontraditional” to “modifiable”. Due to the large amounts of research available on sex, race and age as risk factors for suicidal behaviors, we focused our report on other factors that have the potential to be modified.; Studies which only reported sex, age, or race were not included in the report. However, if a study reporting other factors also reported sex, race, age, we tallied those up but did not go into detail discussing results of these factors in this report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | For the domains categorized under community-level, it would be helpful to state the rationale for categorizing in this way, particularly for homelessness, which seems to be an individual level factor and also which isn’t necessarily bound to a certain region or area. | Categorizing factors was a difficult process as many factors could conceptually fit into multiple categories. The study team, along with content experts and Technical Expert Panel members categorized each factor as best they could, given definitions provided by study authors. We agree with the reviewer and have moved homelessness to the individual domain.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | Table 1. Several of the examples would benefit from clarification or additional detail to ensure accurate categorization. For example, the “barriers to health care” example could be revised to ensure it is specific to the community; otherwise, such barriers would likely be at the individual level (e.g., personal stigma, lack of insurance) or societal level (e.g., societal norms regarding help-seeking). Similarly, it would be worth specifying for “cultural and religious beliefs” that these are within the community. The societal level examples would also benefit from being refined accordingly (e.g., for stigma and lethal means access, this would presumably be more about broad norms or laws that enable these). | We agree, and if specific barriers were judged to be at an individual level, that is where we categorized it in the evidence tables for the review. Table 1 was meant to provide a broad overview of the types of factors that exist, and how they could be categorized based on the Social-Ecological Model. These examples were derived from another systematic review. We have added a footnote to the table to cite where the examples came from.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | Table 2, timing- were studies excluded if it was unclear if the risk factor preceded the suicide/suicide attempt? | Yes.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | How was quality of the assessment methods of suicide attempt and suicide factored into the risk of bias ratings? Could this information be provided outright for future reviews? | We used the QUIPS tool for prognostic studies to rate risk of bias, which does include a domain for outcome assessment. Specifically, the tool asks: “A clear definition of outcome is provided; The method of outcome measurement used is adequately valid and reliable to limit misclassification bias; The method and setting of outcome measurement is the same for all study participants.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - Odd wording p10 ““feeling others’ would be better off I was dead”, probably easiest fix would be removing the apostrophe for others as it is not possessive and adding and if- “better off if I was dead” | This was a typo that has been edited.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - The first 3 paragraphs on page 11 start with the same structure. It would read better if it did not count the number of studies in each but led with the constructs of interest for each. | Thank you for the suggestion.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - The first time STARRS is mentioned (p 11), there is no full title and no description. Will the reader know what this is? | This has been edited to spell out acronym and describe the STARRS study briefly.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - STARRS is not included in the acronyms list (p 16) | Thank you, this has been added to the table.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - I would suggest you separate out risk from protective factors in table 4 (p 26) as it is confusing to try to quickly determine which variables might be considered risk and which are protective | This table is intended to show a summary of what was reported. It was often uncertain if a factor was a risk or protective factor, as many results were mixed.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - Love appendix C (p 46) but probably needs editing | Thank you, you may be the first reviewer to have noticed our template placeholder language (or at least comment on it). Appendix has been edited.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | Inconsistent use of ‘risk of bias’ and ‘ROB’, not sure it matters, just wanted to point out. some minor grammar issues (see highlights) - pg 3 line 51 - ‘better of IF I was dead’. pg 5 line 26 - ‘history OF TBI’. pg 6 line 38 - unclear verbiage. pg 7 line 50 - accompany used as adjective here so consider ‘accompanying evidence map’; verb tense; ‘as well AS’. pg 19 line 10 - perhaps a misplaced ‘I’. pg 20 - consider adding box for ‘societal level’ and denoting 0 studies. pg 26 line 5 - BMI, consider clarify body mass index, only clarified in footnote of table. | Thank you, all of these corrections have been made.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | The review is comprehensive and analysis excellent. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | I had the following questions/comments:; 1) what is the rationale for limiting the studies to the past 10 years? Especially as this will bias results towards studies of OEF/OIF Veterans/soldiers. Valuable information for other cohorts (e.g. Vietnam; which are especially at high risk for suicide death/attempts) may not be fully captured within this time frame | We limited our search from 2011 because VA ESP conducted a review on suicide risk factors which was published in 2012, which used similar inclusion criteria to this review. Our report does include Veterans from many different service-eras, as age of participants was not an exclusion criterion.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | 2) some of the designations for individual, social and community were not clear to me. For example: In the initial description of the model, social isolation is listed as an example of an “individual” factor (pg 10) but in the listing on table 4, is now under social category. Similarly, not sure how homelessness is under community as housing problems seems closer to legal and financial problems; which are individual factors. | Thank you for pointing out these discrepancies. Categorizing factors was a difficult process as many factors could conceptually fit into multiple categories. The study team, along with content experts and the Technical Expert Panel members categorized each factor as best they could given the definition provided by study authors. Table 1 is just an example of how factors could be categorized. We’ve added some clarity to the report to indicate that Table 1 is just an example. In our report, the 1 study that reported on “social isolation” grouped it together with “perceived burdensomeness” and “thwarted belongingness”; therefore, we categorized it as a relational factor in this instance. We agree with the reviewer and have move homelessness to the individual domain.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | 3) I struggled conceptually with the decision to limit the review to general population and decision to not include individuals known to be at heightened risk (e.g. depression, mental illness and suicide history). However, the report contains much data exactly on these individuals. For example on, pg 18, “10 studies examined the association of previous suicide attempts or ideation with future attempt or suicide”. Plus in table 4, 22 studies looked at “other mental illness”. A better clarification of why these studies were included in needed. In essence, the review’s finding confirm what we knew about elevated suicide risk pertaining to history of mental illness and previous attempt. I think there needs to be a better synthesis of the findings with what is already known and the decision to exclude these individuals in the review.; Also, perhaps its a separate question, but would be extremely important to know what are the risk and protective factors of individuals at risk for suicide (not just general population)… as these are the individuals likely to have suicide event(s). | We were tasked with identifying risk or protective factors in a general population (eg, <50% were already at elevated risk for suicide). However, previous suicide attempt or other well-known risk factors were still reported within the general population, which is why they were included in the review as identified factors. We agree, that it is important to understand risk and protective factors of at-risk individuals, however, that was outside the scope of this review.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | 4) I completely agree with the need for studies examining combination of factors. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 1, line 20 (and throughout): Social-Ecological Model vs. Socio-Ecological Framework. I’m assuming these are the same? | These are the same, we have edited the report to reference the Social-Ecological Model for consistency.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 4: It should be mentioned (and it may be in the body of the report) that homelessness is the result of both individual and structural factors and can be classified as both an individual- and community-level risk factor (depending on how it is conceptualized in the research). In addition, I think it would be useful to define the societal level of the SEM even if there are no studies that report on this factor. | This is described in the report, as you have noted in your following comment.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 18, line 25: PTSD was not consistently associated with suicide, meaning sometimes it was and sometimes it was not? | Correct. Results were mixed.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 19, line 10: A word seems to be missing? | Thank you, this was corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 19, lines 25-28: I do not understand this sentence. | This sentence was edited for clarity.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 19, Table 4: The authors mention in Table 2 that “studies including >50% participants with increased risk of suicide due to prior suicide attempters or with specific mental or physical health conditions known to increase suicide risk” are excluded. But, clearly, previous suicide attempt/suicidal ideation is an individual-level risk factor included in 10 studies. So, just to be clear: if less than 50% of the sample had that indicator, the study was included; if more than 50%, the study was excluded? | Correct, we were tasked with identifying risk or protective factors in a general population (eg, <50% were already at elevated risk for suicide). However, previous suicide attempt or other well-know risk factors were still reported, which is why they were included in the review as identified factors.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Table 5 provides a nice snapshot of the results! | Thank you!
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 28, line 24: The brief description here of the societal level of the SEM addresses my comment on page 4. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Table 6: I find it interesting that tobacco use shows up as particularly “risky” for suicide-related outcomes. I wonder if it would be useful to break out alcohol, tobacco, and other drug use into 3 categories so readers can see which substances are associated with risk as that seems to vary across studies (and certainly has different implications for interventions or explanations/theories for increased suicide risk). | We agree, it would be useful to break out into separate categories, unfortunately, several included studies grouped these together as a generic “substance abuse” or used diagnostic codes for Substance Abuse Disorder, and we didn’t have enough information to make this more granular.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 32, line 54: I wonder if it would be useful to provide a summary of how the outcomes—suicide death and suicide attempt—were reported. Or, at least note what the differences were (e.g., timing of the event, data used to assess the event, etc.). This could be useful for researchers in determining the appropriate way to assess such outcomes in future work. | The vast majority of included studies used administrative data for suicide death (NDI, VA, etc.); suicide attempts were most often captured via self-report survey data.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 35, lines 52-54: When the authors discuss “factor classifications and definitions,” are they referring to risk factors? So, are the authors suggesting that there may need to be a more uniformly agreed upon way to code or categorize variables that may predict suicide? I agree and, if that is the authors’ intent, I think it would be useful to state that in a more concrete and explicit way. | Thank you, we have elaborated on this sentence in the report to adequately convey this thought.