# APPENDIX B QUALITY ASSESSMENT FOR ELIGIBLE PUBLICATIONS

Study, Year | Study Participation | Study Attrition | Prognostic Factor Measurement | Outcome Measurement | Study Confounding | Statistical Analysis and Reporting | Overall Risk of Bias
Alexander, 2014^67^ | High | Moderate | Low | Low | High | Low | High
Barry, 2018^41^ | Low | NA | Low | Low | Low | Low | Low
Barth, 2016^31^ | Low | NA | Moderate | Low | Moderate | Low | Moderate
Bernecker, 2019^6^ | Moderate | Moderate | Low | Moderate | Moderate | Moderate | Moderate
Bishop, 2020^49^ | Low | NA | Moderate | Moderate | Low | Low | Moderate
Black, 2011^68^ | Moderate | NA | High | Low | Moderate | Moderate | High
Blow, 2012^50^ | Low | NA | Low | Low | Moderate | Low | Moderate
Bohnert, 2014^7^ | Low | Low | Low | Low | Low | Low | Low
Bohnert, 2017^42^ | Low | NA | Low | Low | Low | Low | Low
Bullman, 2018^12^ | Low | NA | Low | Low | Moderate | Low | Moderate
Bullman, 2019^51^ | Low | NA | Low | Low | Moderate | Low | Moderate
Chu, 2020^8^ | Moderate | Moderate | Moderate | Moderate | Low | Low | Moderate
Conner, 2013^52^ | Low | NA | Low | Low | Moderate | Low | Moderate
Cooper, 2020^43^ | Low | NA | Low | Low | Low | Low | Low
Cusack, 2020^30^ | Low | NA | Low | Low | Low | Low | Low
Dempsey, 2019^53^ | Low | Moderate | Low | Low | Low | Low | Moderate
Dobscha, 2014^13^ | Low | NA | Moderate | Moderate | Low | Low | Moderate
Doran, 2016^14^ | Low | NA | Low | Low | High | Moderate | Moderate
Finley, 2015^15^ | Low | NA | Low | Low | Moderate | Moderate | Moderate
Goodin, 2019^16^ | Low | NA | Low | Low | Moderate | Low | Moderate
Gradus, 2013^69^ | Low | High | Low | Moderate | High | Low | High
Griffith, 2017^17^ | Low | NA | Low | Low | Moderate | Low | Moderate
Hoffmire, 2015^54^ | Moderate | NA | Low | Low | High | Moderate | Moderate
Hostetter, 2019^55^ | Low | NA | Low | Low | Moderate | Low | Moderate
Hyman, 2012^18^ | Low | Low | Low | Low | Moderate | High | Moderate
Ilgen, 2012^36^ | Low | NA | Low | Low | Low | Low | Low
Ilgen, 2013^56^ | Low | NA | Low | Low | Moderate | Low | Moderate
Kang, 2015^19^ | Low | NA | Low | Low | Moderate | Low | Moderate
Katz, 2012^57^ | Moderate | NA | Low | Moderate | High | Moderate | Moderate
Kimerling, 2016^20^ | Low | NA | Low | Low | Moderate | Low | Moderate
LeardMann, 2013^9^ | Moderate | Low | Low | Low | Low | Low | Moderate
Louzon, 2016^35^ | Low | NA | Low | Low | Low | Low | Low
Lynch, 2020^44^ | Low | NA | Moderate | Low | Moderate | Low | Moderate
Martz, 2018^58^ | Low | NA | Low | Low | Moderate | Low | Moderate
McCarthy, 2014^59^ | Moderate | NA | Low | Low | Moderate | Low | Moderate
McCarthy, 2019^70^ | Low | NA | High | Low | High | Low | High
Naifeh, 2017^10^ | Low | Moderate | Low | Low | Moderate | Low | Moderate
Nock, 2017^71^ | Moderate | Moderate | High | Low | High | Low | High
Palframan, 2020^27^ | Low | NA | Low | Low | Low | Low | Low
Phillips, 2017^11^ | Low | Low | Low | Low | Low | Low | Low
Ravindran, 2020^60^ | Low | NA | Low | Low | Moderate | Low | Moderate
Reger, 2015^45^ | Low | NA | Low | Low | Low | Low | Low
Reger, 2017^72^ | Moderate | NA | Moderate | Low | High | Moderate | High
Riberiro, 2017^61^ | Low | NA | Low | Low | Moderate | Moderate | Moderate
Rosellini, 2017^21^ | Moderate | NA | Low | Low | Low | Low | Moderate
Ryan, 2020^62^ | Low | NA | Low | Low | Moderate | Low | Moderate
Schinka, 2016^63^ | Moderate | NA | Moderate | Low | High | Low | Moderate
Schinka, 2018^64^ | Moderate | NA | Moderate | Low | High | Moderate | Moderate
Shen, 2016^28^ | Low | NA | Low | Low | Low | Low | Low
Shiner, 2020^46^ | Low | NA | Low | Low | Low | Low | Low
Skopp, 2016^22^ | Low | NA | Moderate | Low | High | Moderate | Moderate
Thomsen, 2011^73^ | Moderate | Moderate | High | High | Low | Low | High
Trofimovich, 2013^47^ | Low | NA | Low | Low | Low | Low | Low
Ursano, 2015^65^ | Low | NA | Low | Moderate | Low | Low | Moderate
Ursano, 2016^66^ | Low | NA | Low | Moderate | Low | Low | Moderate
Ursano, 2017a^48^ | Low | NA | Low | Low | Low | Low | Low
Ursano, 2017b^33^ | Low | NA | Low | Moderate | Low | Low | Moderate
Ursano, 2017c^32^ | Low | NA | Moderate | Moderate | Low | Low | Moderate
Ursano, 2018a^23^ | Low | NA | Low | Moderate | Low | Low | Moderate
Ursano, 2018b^25^ | Low | NA | Low | Moderate | High | Low | Moderate
Ursano, 2018c^24^ | Low | NA | Low | Moderate | Low | Low | Moderate
Ursano, 2018d^26^ | Low | NA | Moderate | Moderate | Low | Low | Moderate
Zuromski, 2019^74^ | Moderate | Moderate | High | Low | Low | Moderate | High