# APPENDIX A SEARCH STRATEGIES

## OVID MEDLINE, EMBASE AND PSYCINFO

1 | Suicide/ or Suicide, Attempted/ or suicide.mp.
2 | (suicide$1 or suicidal or suicidality).ti, ab.
3 | (suicide$1 adj (prevent or prevention or preventing or prevents)).ti,ab.
4 | Or/1-3
5 | Risk Factors/
6 | Risk.mp.
7 | 5 or 6
8 | Veterans/ or Military Personnel/
9 | Veteran$1 or (military adj person*)).ti,ab.
10 | 8 or 9
11 | 4 and 7 and 10
12 | Limit 11 to English language
13 | Limit 12 to yr=”2011-current”
14 | Limit 13 to (case reports or clinical conference of comment or editorial or letter or news or newspaper article)
15 | 13 not 14
16 | (child8 or adolescen*).ti,ab.
17 | 15 not 16
18 | Limit 17 to humans
19 | Remove duplicates from 18

## SOCIOLOGICAL ABSTRACTS

((mainsubject.Exact(“veterans” OR “veteran/veterans” OR “military” OR “military personnel”)) or (ab(veteran OR military) OR ti(veteran OR military))) and (mainsubject.Exact(“suicides & suicide attempts” OR “suicide, attempted” OR “suicide” OR “suicide/suicides/suicidal”) OR ab(suicide OR suicidality OR suicidal) OR ti(suicide OR suicidality OR suicidal)) and (mainsubject.Exact(“risk factors”) OR ab(RISK FACTOR) OR ti(RISK FACTOR))