# REFERENCES

1 Centers for Disease Control and Prevention; National Center for Health Statistics. Leading Causes of Death. https://www.cdc.gov/nchs/fastats/leading-causes-of-death.htm. Accessed 11/20/20.
2 Office of Mental Health and Suicide Prevention. National Veteran Suicide Prevention Annual Report. US Department of Veterans Affairs;2020. https://www.mentalhealth.va.gov/docs/data-sheets/2020/2020-National-Veteran-Suicide-Prevention-Annual-Report-11-2020-508.pdf.
3 U.S. Department of Veterans Affairs, QUERI Partnered Evaluation Initiative. Evaluation of a Caring Letters Suicide Prevention Campaign. https://www.queri.research.va.gov/about/factsheets/suicide-prevention-PEI.pdf. Published 2019. Accessed 9/24/20.
4 Kessler RC, Hwang I, Hoffmire CA, . Developing a practical suicide risk prediction model for targeting high-risk patients in the Veterans health Administration. Int J Methods Psychiatr Res. 2017;26(3):e1575.
5 U.S. Department of Veterans Affairs. VA National Suicide Data Report 2005–2016. 2018. file:///Users/shahnazsultan/Dropbox/www.mentalhealth.va.gov/docs/data-sheets/OMHSP_National_Suicide_Data_Report_2005-2016_508.pdf.
6 U.S. Department of Veterans Affairs. National Strategy for Preventing Veteran Suicide 2018–2028. https://www.mentalhealth.va.gov/suicide_prevention/docs/Office-of-Mental-Health-and-Suicide-Prevention-National-Strategy-for-Preventing-Veterans-Suicide.pdf.
7 U.S. Department of Veterans Affairs. PREVENTS. The Presidents’ Roadmap to Empower Veterans and End a National Tragedy of Suicide. 2020. https://www.va.gov/PREVENTS/docs/PRE-007-The-PREVENTS-Roadmap-1-2_508.pdf.
8 Higgins JP, Altman DG, Gotzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. Bmj. 2011;343:d5928.22008217
9 Tufanaru C MZ, Aromataris E, Campbell J, Hopp L. Chapter 3: Systematic reviews of effectiveness. In: Aromataris E MZ, ed.: The Joanna Briggs Institute; 2017: https://reviewersmanual.joannabriggs.org/.
10 Guyatt GH, Oxman AD, Kunz R, Vist GE, Falck-Ytter Y, Schünemann HJ. What is “quality of evidence” and why is it important to clinicians? Bmj. 2008;336(7651):995–998.18456631
11 Stone DM, Holland, K.M., Bartholow, B., Crosby, A.E., Davis, S., and Wilkins, N. Preventing Suicide: A Technical Package of Policies, Programs, and Practices. Atlanta, GA National Center for Injury Prevention and Control, Centers for Disease Control and Prevention;2017.
12 Montgomery AE, Dichter M, Byrne T, Blosnich J. Intervention to address homelessness and all-cause and suicide mortality among unstably housed US Veterans, 2012-2016. J Epidemiol Community Health. 2020.
13 Yip PS, Law CK, Fu KW, Law YW, Wong PW, Xu Y. Restricting the means of suicide by charcoal burning. Br J Psychiatry. 2010;196(3):241–242.20194548
14 Chen YY, Chen F, Chang SS, Wong J, Yip PS. Assessing the Efficacy of Restricting Access to Barbecue Charcoal for Suicide Prevention in Taiwan: A Community-Based Intervention Trial. PLoS One. 2015;10(8):e0133809.26305374
15 Jo SJ, Yun MI, Lee MS. Effects of a province-based strategy to prevent suicide using charcoal burning: A preliminary time series analysis. Psychiatry Investigation. 2019;16(8):621–624.31446687
16 Sinyor M, Schaffer A, Redelmeier DA, . Did the suicide barrier work after all? Revisiting the Bloor Viaduct natural experiment and its impact on suicide rates in Toronto. BMJ Open. 2017;7(5):e015299.
17 Sinyor M, Levitt AJ. Effect of a barrier at Bloor Street Viaduct on suicide rates in Toronto: natural experiment. Bmj. 2010;341:c2884.20605890
18 Perron S, Burrows S, Fournier M, Perron PA, Ouellet F. Installation of a bridge barrier as a suicide prevention strategy in Montreal, Quebec, Canada. Am J Public Health. 2013;103(7):1235–1239.23678905
19 Law CK, Sveticic J, De Leo D. Restricting access to a suicide hotspot does not shift the problem to another location. An experiment of two river bridges in Brisbane, Australia. Aust N Z J Public Health. 2014;38(2):134–138.24690051
20 Hemmer A, Meier P, Reisch T. Comparing Different Suicide Prevention Measures at Bridges and Buildings: Lessons We Have Learned from a National Survey in Switzerland. PLoS One. 2017;12(1):e0169625.28060950
21 Law CK, Yip PS. An economic evaluation of setting up physical barriers in railway stations for preventing railway injury: evidence from Hong Kong. J Epidemiol Community Health. 2011;65(10):915–920.21282146
22 Chung YW, Kang SJ, Matsubayashi T, Sawada Y, Ueda M. The effectiveness of platform screen doors for the prevention of subway suicides in South Korea. J Affect Disord. 2016;194:80–83.26803779
23 Ueda M, Sawada Y, Matsubayashi T. The effectiveness of installing physical barriers for preventing railway suicides and accidents: evidence from Japan. J Affect Disord. 2015;178:1–4.25770476
24 Matsubayashi T, Sawada Y, Ueda M. Does the installation of blue lights on train platforms prevent suicide? A before-and-after observational study from Japan. J Affect Disord. 2013;147(1–3):385–388.22980401
25 Matsubayashi T, Sawada Y, Ueda M. Does the installation of blue Lights on train platforms shift suicide to another station?: Evidence from Japan. J Affect Disord. 2014;169:57–60.25151192
26 Ichikawa M, Inada H, Kumeji M. Reconsidering the effects of blue-light installation for prevention of railway suicides. J Affect Disord. 2014;152–154:183–185.
27 Mishara BL, Martin N. Effects of a comprehensive police suicide prevention program. Crisis. 2012;33(3):162–168.22450038
28 Knox KL, Pflanz S, Talcott GW, . The US Air Force suicide prevention program: implications for public health policy. Am J Public Health. 2010;100(12):2457–2463.20466973
29 Shelef L, Tatsa-Laur L, Derazne E, Mann JJ, Fruchter E. An effective suicide prevention program in the Israeli Defense Forces: A cohort study. Eur Psychiatry. 2016;31:37–43.26657599
30 Doran CM, Ling R, Gullestrup J, Swannell S, Milner A. The Impact of a Suicide Prevention Strategy on Reducing the Economic Cost of Suicide in the New South Wales Construction Industry. Crisis. 2016;37(2):121–129.26695869
31 Schilling EA, Aseltine RH, Jr., James A. The SOS Suicide Prevention Program: Further Evidence of Efficacy and Effectiveness. Prev Sci. 2016;17(2):157–166.26314868
32 Wasserman D, Hoven CW, Wasserman C, . School-based suicide prevention programmes: the SEYLE cluster-randomised, controlled trial. Lancet. 2015;385(9977):1536–1544.25579833
33 Milner A, Aitken Z, Law PCF, . The relationship between an electronic mental health stigma campaign and suicidal thoughts and behaviours: a two-arm randomized controlled trial in the Australian construction industry. Health promotion international. 2019;12.
34 Sareen J, Isaak C, Bolton SL, . Gatekeeper training for suicide prevention in First Nations community members: a randomized controlled trial. Depress Anxiety. 2013;30(10):1021–1029.23761133
35 Walrath C, Garraza LG, Reid H, Goldston DB, McKeon R. Impact of the Garrett Lee Smith youth suicide prevention program on suicide mortality. Am J Public Health. 2015;105(5):986–993.25790418
36 Godoy Garraza L, Walrath C, Goldston DB, Reid H, McKeon R. Effect of the Garrett Lee Smith Memorial Suicide Prevention Program on Suicide Attempts Among Youths. JAMA Psychiatry. 2015;72(11):1143–1149.26465226
37 Godoy Garraza L, Kuiper N, Goldston D, McKeon R, Walrath C. Long-term impact of the Garrett Lee Smith Youth Suicide Prevention Program on youth suicide mortality, 2006-2015. J Child Psychol Psychiatry. 2019;60(10):1142–1147.31066462
38 Stack S. Crisis Phones - Suicide Prevention Versus Suggestion/Contagion Effects. Crisis. 2015;36(3):220–224.26122258
39 Till B, Sonneck G, Baldauf G, Steiner E, Niederkrotenthaler T. Reasons to love life. Effects of a suicide-awareness campaign on the utilization of a telephone emergency line in Austria. Crisis. 2013;34(6):382–389.23942384
40 Matsubayashi T, Ueda M, Sawada Y. The effect of public awareness campaigns on suicides: evidence from Nagoya, Japan. J Affect Disord. 2014;152–154:526–529.
41 Oyama H, Sakashita T. Long-Term Effects of a Screening Intervention for Depression on Suicide Rates among Japanese Community-Dwelling Older Adults. Am J Geriatr Psychiatry. 2016;24(4):287–296.26796924
42 Oyama H, Sakashita T. Community-based screening intervention for depression affects suicide rates among middle-aged Japanese adults. Psychol Med. 2017;47(8):1500–1509.28193313
43 Dezso D, Konrad N, Seewald K, Opitz-Welke A. Implementation of a Suicide Risk Screening Instrument in a Remand Prison Service in Berlin. Front Psychiatry. 2018;9:665.30618858
44 Collings S, Jenkin G, Stanley J, McKenzie S, Hatcher S. Preventing suicidal behaviours with a multilevel intervention: a cluster randomised controlled trial. BMC Public Health. 2018;18(1):140.29338723
45 Hegerl U, Maxwell M, Harris F, . Prevention of suicidal behaviour: Results of a controlled community-based intervention study in four European countries. PLoS One. 2019;14(11):e0224602.31710620
46 Hegerl U, Mergl R, Havers I, . Sustainable effects on suicidality were found for the Nuremberg alliance against depression. Eur Arch Psychiatry Clin Neurosci. 2010;260(5):401–406.19921299
47 Szekely A, Konkoly Thege B, Mergl R, . How to decrease suicide rates in both genders? An effectiveness study of a community-based intervention (EAAD). PLoS One. 2013;8(9):e75081.24086443
48 Hubner-Liebermann B, Neuner T, Hegerl U, Hajak G, Spiessl H. Reducing suicides through an alliance against depression? Gen Hosp Psychiatry. 2010;32(5):514–518.20851273
49 Ono Y, Sakai A, Otsuka K, . Effectiveness of a multimodal community intervention program to prevent suicide and suicide attempts: a quasi-experimental study. PLoS One. 2013;8(10):e74902.24130673
50 Lai CCS, Law YW, Shum AKY, Ip FWL, Yip PSF. A Community-Based Response to a Suicide Cluster. Crisis. 2020;41(3):163–171.31418310
51 Kato R, Okada M. Can Financial Support Reduce Suicide Mortality Rates? Int J Environ Res Public Health. 2019;16(23):29.
52 Lee SU, Park JI, Lee S, Oh IH, Choi JM, Oh CM. Changing trends in suicide rates in South Korea from 1993 to 2016: a descriptive study. BMJ Open. 2018;8(9):e023144.
53 Nakanishi M, Yamauchi T, Takeshima T. National strategy for suicide prevention in Japan: impact of a national fund on progress of developing systems for suicide prevention and implementing initiatives among local authorities. Psychiatry Clin Neurosci. 2015;69(1):55–64.25041482
54 Law YW, Yeung TL, Ip FWL, Yip PSF. Evidence-Based Suicide Prevention: Collective Impact of Engagement with Community Stakeholders. J Evid Based Soc Work (2019). 2019;16(2):1–17.
55 Lung FW, Liao SC, Wu CY, Lee MB. The effectiveness of suicide prevention programmes: urban and gender disparity in age-specific suicide rates in a Taiwanese population. Public Health. 2017;147:136–143.28404489
56 Ross V, Koo YW, Kolves K. A suicide prevention initiative at a jumping site: A mixed-methods evaluation. EClinicalMedicine. 2020;19 (no pagination).
57 Lockley A, Cheung YT, Cox G, . Preventing suicide at suicide hotspots: a case study from Australia. Suicide Life Threat Behav. 2014;44(4):392–407.25250406
58 Nakanishi M, Endo K, Ando S, Nishida A. The Impact of Suicide Prevention Act (2006) on Suicides in Japan. Crisis. 2020;41(1):24–31.31066309
59 Okada M, Hasegawa T, Kato R, Shiroyama T. Analysing regional unemployment rates, GDP per capita and financial support for regional suicide prevention programme on suicide mortality in Japan using governmental statistical data. BMJ Open. 2020;10(8):e037537.
60 Page A, Taylor R, Gunnell D, Carter G, Morrell S, Martin G. Effectiveness of Australian youth suicide prevention initiatives. Br J Psychiatry. 2011;199(5):423–429.22045948
61 Taylor-Rodgers E, Batterham PJ. Evaluation of an online psychoeducation intervention to promote mental health help seeking attitudes and intentions among young adults: randomised controlled trial. J Affect Disord. 2014;168:65–71.25038293
62 Rogers ML, Schneider ME, Gai AR, Gorday JY, Joiner TE. Evaluation of two web-based interventions in reducing the stigma of suicide. Behav Res Ther. 2018;109:49–55.30107279
63 Voss WD, Kaufman E, O’Connor SS, Comtois KA, Conner KR, Ries RK. Preventing addiction related suicide: a pilot study. J Subst Abuse Treat. 2013;44(5):565–569.23375569
64 Jacobson JM, Osteen PJ, Sharpe TL, Pastoor JB. Randomized Trial of Suicide Gatekeeper Training for Social Work Students. Research on Social Work Practice. 2012;22(3):270–281.
65 Perceval M, Reddy P, Ross V, Joiner T, Kolves K. Evaluation of the SCARF Well-Being and Suicide Prevention Program for Rural Australian Communities. J Rural Health. 2020;36(2):247–254.31059168
66 Shekelle P, Bagley S, Munjas B. Strategies for suicide prevention in veterans. 2010.
67 Graetz N, Preston SH, Peele M, Elo IT. Ecological factors associated with suicide mortality among non-Hispanic whites. BMC Public Health. 2020;20(1):1339.32883238
68 National Institute of Mental Health. Suicide. https://www.nimh.nih.gov/health/statistics/suicide.shtml. Accessed November 3, 2020.
69 Klonsky ED, May AM, Saffer BY. Suicide, Suicide Attempts, and Suicidal Ideation. Annu Rev Clin Psychol. 2016;12:307–330.26772209
70 Paykel ES, Myers JK, Lindenthal JJ, Tanner J. Suicidal feelings in the general population: a prevalence study. Br J Psychiatry. 1974;124(0):460–469.4836376
71 Harris FM, Maxwell M, O’Connor R, . Exploring synergistic interactions and catalysts in complex interventions: longitudinal, mixed methods case studies of an optimised multi-level suicide prevention intervention in four european countries (Ospi-Europe). BMC Public Health. 2016;16:268.26979461
72 Godoy Garraza L, Peart Boyce S, Walrath C, Goldston DB, McKeon R. An Economic Evaluation of the Garrett Lee Smith Memorial Suicide Prevention Program. Suicide Life Threat Behav. 2018;48(1):3–11.27982449
73 Saeheim A, Hestetun I, Mork E, Nrugham L, Mehlum L. A 12-year National Study of Suicide by Jumping From Bridges in Norway. Arch Suicide Res. 2017;21(4):568–576.27309998
74 Finney EJ, Buser SJ, Schwartz J, Archibald L, Swanson R. Suicide prevention in fire service: The Houston Fire Department (HFD) model. Aggression and Violent Behavior. 2015;21:1–4.
75 Han J, Batterham PJ, Calear AL, Wu Y, Xue J, Spijker BAJv. Development and pilot evaluation of an online psychoeducational program for suicide prevention among university students: A randomised controlled trial. Internet Interventions. 2018;12:111–120.30135775
76 Dueweke AR, Bridges AJ. The effects of brief, passive psychoeducation on suicide literacy, stigma, and attitudes toward help-seeking among Latino immigrants living in the United States. Stigma and Health. 2017;2(1):28–42.
77 Freedenthal S. Adolescent help-seeking and the Yellow Ribbon Suicide Prevention Program: an evaluation. Suicide Life Threat Behav. 2010;40(6):628–639.21198332
78 Gravesteijn C, Diekstra R, Sklad M, de Winter M. The Effects of a Dutch School-Based Social and Emotional Learning Programme (SEL) on Suicidality in Adolescents. International Journal of Mental Health Promotion. 2011;13(4):4–16.
79 Kennedy AJ, Brumby SA, Versace VL, Brumby-Rendell T. The ripple effect: a digital intervention to reduce suicide stigma among farming men. BMC Public Health. 2020;20(1):813.32471501
80 Smith-Osborne A, Maleku A, Morgan S. Impact of applied suicide intervention skills training on resilience and suicide risk in army reserve units. Traumatology. 2017;23(1):49–55.
81 Wang J, Hausermann M, Berrut S, Weiss MG. The impact of a depression awareness campaign on mental health literacy and mental morbidity among gay men. J Affect Disord. 2013;150(2):306–312.23683994
82 King KA, Strunk CM, Sorter MT. Preliminary effectiveness of surviving the teens((R)) suicide prevention and depression awareness program on adolescents’ suicidality and self-efficacy in performing help-seeking behaviors. J Sch Health. 2011;81(9):581–590.21831072
83 Nakanishi M, Endo K. National Suicide Prevention, Local Mental Health Resources, and Suicide Rates in Japan. Crisis. 2017;38(6):384–392.28748710
84 Pirruccello LM. Preventing adolescent suicide: a community takes action. J Psychosoc Nurs Ment Health Serv. 2010;48(5):34–41.
85 Matsubayashi T, Ueda M. The effect of national suicide prevention programs on suicide rates in 21 OECD nations. Soc Sci Med. 2011;73(9):1395–1400.21940085