# SUMMARY AND DISCUSSION

Using the CDC framework of community-based approaches to suicide prevention, we found that reducing access to lethal means, implementing programs that influence organizational policies and culture in police workplace settings, and screening for depression in the community may reduce suicide deaths. However, we found uncertain or no evidence for reducing suicide deaths for other interventions as standalone interventions, including public awareness and education campaigns, crisis hotlines, and gatekeeper training. In high school students, social-emotional learning programs, gatekeeper training, and screening may reduce suicide attempts but had uncertain effects on suicide deaths. Additionally, we found inconsistent results for comprehensive, multi-strategy interventions. We found an increase in suicides after implementation of a multi-strategy intervention in New Zealand but found a decrease in suicides associated with the European Alliance Against Depression Program.

Our report builds on a 2009 VA-ESP report.^66^ These authors focused on suicide prevention strategies among Veterans or military personnel and evaluated: educational awareness programs, screening for high-risk individuals, pharmacotherapy, psychotherapy, restriction of means, media reporting, and multi-component interventions (eg the U.S. Air Force). They summarized evidence from 1966-2008 and concluded that multi-component interventions in military personnel may reduce suicide risk. They also concluded that restriction of access to lethal means may reduce cause-specific suicides, although its effect on total suicides was less clear. The authors found insufficient data about community-based suicide prevention interventions and no studies assessing hotlines, outreach programs, peer counseling, treatment coordination programs, and new counseling programs.

Our inability to determine effective components of multi-strategy interventions limits the ability to adapt or implement the effective interventions among Veterans or other settings. While some standalone strategies may reduce suicide deaths or attempts; it is unclear why interventions that combine multiple strategies into comprehensive programs showed inconsistent results. One possible explanation is that it is important to target specific populations or settings and use tailored interventions. For example, the “Together for Life” program targeting the police workplace and the Signs of Suicide or Youth Awareness of Mental Health program targeting high school students, were associated with reductions in suicide deaths or attempts.^27,31,32^ Another possible explanation is that multi-strategy programs are arguably more complex and the fidelity of the individual strategies was not clear.

## LIMITATIONS AND FUTURE RESEARCH

An important limitation of the evidence is the methodological quality of the eligible studies. Drawing conclusions from these studies was challenging due to lack of adequate adjustment for temporal trends in suicide rates or differences between intervention and comparison communities in terms of socioeconomic characteristics and access to lethal means, both of which have been associated with suicide risk.^67^ Additional limitations included the scarcity of evidence for some interventions, lack of detail on the specific elements of each intervention, and limited data on implementation, resource use, or cost. Additionally, we did not find studies that examined the applicability or adaptability of an intervention from 1 setting to another. Few studies examined implementation-related outcomes and thus it is not possible to determine if wider implementation of the included interventions would result in positive outcomes. Higher-quality studies using RCT trial designs may not be feasible for all community- or population-based intervention but could be conducted in organizational workplaces, schools, or other communities. In the absence of RCTs, observational studies with concurrent control groups and adequate adjustment for confounding would provide useful information. Because suicide is rare, having adequate follow-up and sample size is important. Evidence quality would be enhanced by using standardized descriptions of the interventions. More complete intervention descriptions would facilitate replication or evaluation of effective programs. For multi-strategy interventions, a clearer framework to justify and describe the components is needed, as well as an attempt to evaluate individual components. More evidence is needed to see if the success of suicide interventions is population-specific and if specific combinations of interventions are more successful than others. Finally, studies examining interventions’ acceptability, feasibility, effectiveness, and sustainability in US Veterans are needed, particularly those targeting suicide means relevant to Veterans, such as firearms, poisoning, and suffocation.

## APPLICABILITY TO VETERANS

Only 1 study targeted Veterans.^12^ It provided unclear evidence regarding the effect of housing stabilization programs. Studies of interventions influencing organizational policies were conducted in the US Air Force and the Israeli Defense Forces^28,29^ but these may not be directly applicable to Veterans. In addition, while community-based programs to restrict the purchase of charcoal at retail stores may reduce self-immolation, this is not a common method of suicide in the US, where the top 3 suicide methods in 2018 were firearms, suffocation, and poisoning.^68^ Utilizing peers with shared experiences may be an effective strategy to deliver a suicide prevention program for Veterans.

## CONCLUSIONS

Community-based interventions that may reduce suicide deaths include reducing access to lethal means, implementing organizational policies in workplace settings, and screening for depression. It is uncertain if housing stabilization programs, public awareness and education campaigns, crisis hotlines, and gatekeeper training prevent suicide. Evidence was inconsistent for community-based, multi-strategy interventions. The most promising multi-strategy intervention was the European Alliance Against Depression. In high school populations, social-emotional learning programs, gatekeeper training, and screening for at-risk may reduce suicide attempts; however, it is unclear if these interventions reduce suicides. Future studies using randomized designs or observational studies with concurrent controls and appropriate adjustment are needed. Studies are needed to determine which interventions and combinations would be most effective and feasible for US Veterans. Until then community-based approaches to suicide prevention outside of VA health care settings may provide additional opportunities to prevent suicide among Veterans.