# METHODS

## TOPIC DEVELOPMENT

The topic was nominated by VA Health Services Research & Development Service. We worked with the Operational Partners and a Technical Expert Panel to refine the scope, key questions, and inclusion/exclusion criteria. We registered a protocol in PROSPERO (ID 188943).

The key questions (KQ) were:

KQ 1 What are the effects of population- and community-based prevention interventions on suicide attempts and suicide deaths?
  KQ 1a What are the key/common components of the most effective interventions?
  KQ 1b What strategies have been used to deliver, sustain, and improve the quality of the most effective interventions?
  KQ 1c How do the effects vary by differences in community/setting and characteristics of individuals targeted?
KQ 2 What are the potential unintended consequences of population- and community-based prevention interventions?

## SEARCH STRATEGY

We searched MEDLINE, Embase, PsycINFO, Sociological Abstracts, and the Cochrane Database of Systematic Reviews. The search was limited from January 2010 to the end of November 2020 and references published in English-language. We used Medical Subject Headings (MeSH) and title/abstract terms indicative of suicide outcomes and community-based interventions. Exclusions terms related to elementary schools, youth populations, and hospital settings were used (Appendix 1). We reviewed reference lists of systematic reviews.

## STUDY SELECTION

We included studies evaluating population- and community-based interventions for suicide prevention in persons high-school age or older and reporting suicide attempts, suicide deaths, or possible unintended consequences. We excluded studies focused on healthcare systems. We also excluded postvention and media reporting guidelines about suicide because these strategies involve interventions delivered after a suicide has occurred (eg, targeting bereaved families, friends, and their peers). Suicidal ideation was not included as an outcome because the progression from ideation to attempts are distinct phenomena^69^ and community-based interventions tend to focus on prevention of suicide attempts and death. We reported on the following possible unintended or unanticipated consequences: suicide-related stigma, caregiver burden, and switching means of suicide, when applicable. Studies reporting suicide-related stigma among the target population as well as stigma in those who were trained as gatekeepers were included. We required the stigma outcome to be reported based on a scale score, such as the Stigma of Suicide scale, that measured stigmatizing attitudes towards suicidal persons or acts.

We required study designs to be randomized controlled trials (RCTs), observational studies with a concurrent control group, or pre-post observational studies. We included studies conducted in the general community, workplace, schools, military settings, prisons, or suicide hotspots. The inclusion and exclusion criteria are presented in Table 2.

Two investigators independently reviewed titles and abstracts; studies considered possibly eligible by at least 1 reviewer were forwarded for full-text screening. Two investigators independently reviewed full-text articles to determine if they met eligibility criteria. Differences in screening decisions were resolved by consensus or, if needed, discussion with a third reviewer. Studies were screened in DistillerSR (Evidence Partners Inc, Ottawa, Canada).

Table 2 Inclusion and Exclusion Criteria

PICOTS | Inclusion Criteria | Exclusion Criteria
Population | Veteran and non-Veteran populations of high school age or older
Intervention | Population- and community-based interventions to prevent suicide | Pharmacotherapy; Psychotherapy delivered in-person or online; Therapeutic interventions that can be delivered only by licensed health care professionals; Legislation enacted to reduce suicide risk factors; Postvention/suicide bereavement support; Media reporting guidelines; Multi-strategy interventions that relied predominantly on the above excluded interventions
Comparison | Pre-intervention; Concurrent control group
Outcomes | Primary outcomes:; suicide attempts; suicide deaths; Possible unintended consequences:; stigma towards suicide; caregiver burden; switching suicide means
Timing | Any
Setting | Community-based settings (ie., schools, workplace, prisons, military settings, suicide hotspots, general community); Countries with very high Human Development Index
Study Design | RCTs; Observational study with pre-post data and/or concurrent control | Case reports; Narrative reviews; Systematic reviews; Editorials and commentary

PICOTS=population, intervention, control, outcomes, timing, setting/study design; RCT=randomized controlled trial

## QUALITY ASSESSMENT

We assessed risk of bias of studies using instruments applicable to the study design. RCTs were assessed using the Cochrane Risk of Bias 1.0 tool, which includes domains for random sequence generation, allocation concealment, blinding, attrition, and selective outcome reporting.^8^ Cluster RCTs were assessed with several additional domains (ie, recruitment bias, baseline imbalance, and incomplete cluster data). Observational studies were assessed for quality using a modified version of the Joanna Briggs Institute Critical Appraisal Tool for Quasi-Experimental Studies (Appendix 2).^9^ The overall risk of bias of each RCT and observational study was classified as High, Moderate, or Low. We did not extract and analyze the studies classified as high risk of bias. One reviewer independently rated risk of bias and a second reviewer verified. We did not asses risk of bias for studies that only examined stigma towards suicide as an outcome among the participants who were trained as gatekeepers and did not report other eligible outcomes.

## DATA ABSTRACTION

We abstracted information on study characteristics, participants, setting, intervention, control, and outcomes. Our primary outcome was suicide deaths. Additional outcomes were suicide attempts, unintended consequences of the intervention (ie, caregiver burden, stigma towards suicide, and switching suicide means), and cost. We also abstracted suicide attempts and suicide deaths outcomes in any population subgroups of interest, which were sex, age, race, military status, housing status, socioeconomic status, and mental health condition/history of suicide behavior. From the studies that found an intervention to be effective, we abstracted the strategies to deliver, sustain, and improve the intervention. Effective was defined as reducing suicide deaths or attempts based on at least low certainty of evidence. One reviewer abstracted data and a second reviewer verified.

## DATA SYNTHESIS

We modified the CDC framework of summary of strategies and approaches to prevent suicide to categorize the interventions.^11^ Modifications included: 1) adding a category for “public awareness and education campaigns” and a category for “screening for at-risk individuals (outside a health care setting)”; and 2) removing CDC strategies and approaches irrelevant to the current review. Definitions of the CDC strategies and approaches to prevent suicide are in Appendix 3. Interventions were classified as multi-strategy when they spanned more than 1 CDC strategy. We also categorized studies by the setting in which they were delivered. As per the CDC framework, suicide prevention programs targeting “closed communities” such as workplace or military were categorized under Organizational policies and culture. However, we acknowledge that these programs could also have been categorized as multi-strategy. Findings were narratively synthesized across studies due to the heterogeneity in populations, interventions, settings, and outcome reporting. When able to, we calculated risk ratios (RR), absolute risk differences (ARD), and standardized mean differences (SMD) with 95 percent confidence intervals for results from individual studies. Data were analyzed in Comprehensive Meta-Analysis version 3 (Biostat).

## RATING THE BODY OF EVIDENCE

Based on the studies published 2010-2020 and for each intervention and setting, we used the Grading of Recommendations, Assessment, Development, and Evaluation (GRADE) approach to rate the certainty of evidence as high, moderate, low, or very low for the outcomes of suicide deaths, suicide attempts, and suicide-related stigma.^10^ For the studies that evaluated reducing access to lethal means, we rated the certainty of evidence for the outcome of switching suicide methods. Using the GRADE approach, data from observational studies start at low certainty while RCTs start at high. The certainty is adjusted based on factors such as study limitations, inconsistency, indirectness, imprecision, and other considerations. We relied on statistical significance to make judgements about imprecision. Certainty was determined by consensus.

## PEER REVIEW

A draft version of this report was reviewed by technical experts as well as clinical leadership. Their comments and our responses are presented in Appendix 6.