# INTRODUCTION

Suicide is a national public health problem with 48,344 estimated United States (US) deaths in 2018, making it a top-10 leading cause of death.^1^ Despite increased awareness and attention to suicide prevention, suicide rates in the US continue to rise in both the military and general populations. Until 2008, suicides in the general population exceeded US military rates. Presently, however, Veterans are 1.5 times more likely to die by suicide than are members of the general population, after adjusting for age and sex.^2^ In 2018, Veterans represented just 8% of the US adult population and accounted for 13.8% of all suicide deaths.^2^ Reducing suicide among military populations, therefore, is of particular urgency.

The Department of Veterans Affairs (VA) has made suicide prevention a top priority. Substantial VA initiatives focus on identifying and treating Veterans determined to be at risk for fatal and nonfatal suicidal behavior. These initiatives include the Veterans Crisis line as well as prevention programs through the Veterans Health Administration (VHA) like the REACHVET program, Caring Contacts to Veterans, yearly screenings for suicide risk, and hiring Suicide Prevention Coordinators at Medical Centers.^3,4^ These VHA-specific initiatives may account for reduced suicide rates among Veterans who use VA health care compared with those who do not.^5^ However, the majority (two-thirds) of the Veteran population do not use the VA for health care. Strategies that rely on health care systems miss opportunities to reach individuals who do not seek health care preceding suicidal behavior or for whom imminent risk is unknown. Accordingly, the National Strategy for Suicide Prevention released by the Office of the Surgeon General, the National Action Alliance for Suicide Prevention, VA’s National Suicide Prevention Strategy,^6^ and the President’s Roadmap to Empower Veterans and End a National Tragedy of Suicide (PREVENTS) Executive Order^7^ all call for a public health approach to the crisis of suicide. Population- and community-based suicide prevention strategies are complimentary to those implemented in health care settings and hold the promise of reducing suicides and suicide attempts across the full spectrum of suicide risk.

We conducted a systematic review of published literature to address key questions related to the effectiveness and harms of community- and population-level interventions for suicide prevention. We focused on studies conducted outside of health care settings and on interventions not related to the treatment of patients (such as drugs or psychotherapy). The topic was nominated by VA Health Services Research & Development Office with the goal of identifying successful programs that might be adaptable for and applied to US Veterans. To facilitate integration of findings from this review with existing efforts to synthesize and disseminate evidence on community-based suicide prevention programs, we grouped interventions according to the Centers for Disease Control and Prevention (CDC) framework for classifying suicide prevention strategies.^11^ Findings can inform the development of research priorities as well as efforts to design research-driven community-based and population-level approaches to suicide prevention.