# ABBREVIATIONS TABLE

Abbreviation: Definitions
ASIST: Applied Suicide Intervention Skills Training
CDC: Centers for Disease Control and Prevention
COE: Certainty of Evidence
ESP: Evidence Synthesis Program
GLS: Garrett Lee Smith
GRADE: Grading of Recommendations, Assessment, Development, and Evaluation
MeSH: Medical Subject Headings
MISP-NV: Multi-Level Intervention for Suicide Prevention in New Zealand
PREVENTS: President’s Roadmap to Empower Veterans and End a National Tragedy of Suicide
REACHVET: Recovery Engagement and Coordination for Health – Veterans Enhanced Treatment
RCT: Randomized controlled trial
ROB: Risk of Bias
SEYLE: Saving and Empowering Young Lives in Europe
US: United States
VA: Department of Veterans Affairs
VHA: Veterans Health Administration