# APPENDIX 6 PEER REVIEW COMMENTS/AUTHOR RESPONSES

Appendix Table 6-1 Peer Reviewer Comments and Author Responses

Question Text | Reviewer Number | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 5 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 6 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 7 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 8 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 9 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 1 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 3 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 4 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 5 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 6 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 7 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 8 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 9 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 1 | Yes - 2020; National Veteran; Suicide Prevention; Annual Report - i think this was just disseminated | We revised the introduction to use the 2020 National Veteran Suicide Prevention Annual Report when citing statistics.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 3 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 4 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 5 | Yes - Garraza, L. G., Kuiper, N., Goldston, D., McKeon, R., & Walrath, C. (2019). Long-term impact of the Garrett Lee Smith Youth Suicide Prevention Program on youth suicide mortality, 2006–2015. Journal of Child Psychology and Psychiatry, 60(10), 1142–1147. 10.1111/jcpp.13058 31066462 | We incorporated the articles about the Garrett Lee Smith program (specifically Garraza 2019 for long-term suicide deaths, Walrath 2015 for short-term suicide deaths, Garraza 2015 for suicide attempts, and Garraza 2018 for cost-benefit analysis).
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 6 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 7 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 8 | Yes - The review seems to miss most of the Garrett Lee Smith manuscripts. Several are listed in the document to be included. Others are:; Godoy Garraza, L., Kuiper, N., Goldston, D., McKeon, R., & Walrath, C. (2019). Long-term impact of the Garrett Lee Smith Youth Suicide Prevention Program on youth suicide mortality, 2006–2015. Journal of child psychology and psychiatry, 60(10), 1142–1147.31066462; Godoy Garraza, L., Peart Boyce, S., Walrath, C., Goldston, D. B., & McKeon, R. (2018). An economic evaluation of the Garrett Lee Smith memorial suicide prevention program. Suicide and Life-Threatening Behavior, 48(1), 3–11.27982449; Other areas that are missing that surprise me are school based programs including Sources of Strength and SOS. A community approach that is not mentioned is Zero Suicide.; In terms of means, it is surprising nothing on blister packaging versus bulk packaging of psychiatric/other medications was not in the search. | We incorporated the articles about the Garrett Lee Smith program (specifically Garraza 2019 for long-term suicide deaths, Walrath 2015 for short-term suicide deaths, Garraza 2015 for suicide attempts, and Garraza 2018 for cost-benefit analysis).; Regarding school-based programs, we included the Signs of Suicide (SOS) program. It was categorized as a social-emotional learning program. We also included the SEYLE trial in Europe which had 3 arms and were categorized as a social-emotional learning program, gatekeeper training, and screening, respectively. We identified additional school-based programs that we rated as high risk of bias and thus not included in the analysis. Examples of these were the Yellow Ribbon program (categorized as a social-emotional learning program), the Skills for Life program (categorized as a social-emotional learning program), and the Surviving the Teens program (categorized as multi-strategy). Our search did not identify any studies for Sources of Strength.; We excluded Zero Suicide because this intervention takes place in a healthcare system.; Our search did not identify any eligible studies on blister packaging versus bulk packaging.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 9 | No | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Misc but in the Intro line 23 there is a sentence saying… “use of suicide prevention coordinators” which might be revised to something like installing and supporting; the word “use” seemed somehow less than accurate. in terms of references, i mention above the newly released 2020 report.; p 2 line 53, “reduce” might read better to revise to “reduction of…”; Assessment of bias and grading system are highly appreciated.; Notes about Mates in Construction cost vs savings - is the huge payoff true? that seems immense IF i am reading it correctly.; I am quite taken with the conclusion of what seems not to be working: public awareness campaigns, crisis hotlines, and gatekeeper - makes 1 pause about | We revised the wording on line 23.; We revised the introduction to use the 2020 National Veteran Suicide Prevention Annual Report when citing statistics.; We revised the wording on line 53.; For Mates in Construction, the $4.60 benefit-cost ratio is true, as reported. We added information about the assumptions used in the model.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Very minor comment: page 9, line 36-37 may be missing a word or phrase? | We revised the wording on line 36-37.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | Very useful and important study.; page 2, line 16. Missing a period. | We added a period on line 16.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | The statistics in the introduction regarding the proportion of veterans in the general population and their contribution to US suicide deaths is wrong (line 17). I looked at your citation - the VA suicide data report which cites different statistics … please check again and revise. | We revised the statistics on line 17. We also updated them with the data in the 2020 National Veteran Suicide Prevention Annual Report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | This review conveys a wealth of information regarding the effectiveness of community-based and public health strategies to prevent suicide. This review appears to have been well-executed, with sound methods. The content is comprehensive, and the conclusions both succinct and nuanced.; One question concerned the categorization of interventions under specific strategies vs as multi-component interventions. The interventions listed under “Organizational Policies and Culture” (p. 26-27) appear to be somewhat similar to the multi-component interventions in that they involve multiple components (eg, telephone hotline, gatekeeper training, education, screening, lethal means reduction), but are distinct in that the setting of the intervention is the workplace and/or the population is more circumscribed. Although this is indeed discussed later (p. 57-58), it would be helpful to understand the decision process by which interventions were categorized into a specific strategy/approach (creating protective environments), as opposed to “multiple strategies” (with workplace as the setting).; On a somewhat related note, the SEYLE study was included under 3 different intervention strategies. Did SEYLE parse out the different intervention strategies (social-emotional learning, gatekeeper training, and screening) and evaluate them separately? If not, this seems like it would be more appropriately classified as a multi-component intervention, particularly given the findings and conclusions about the multi-component interventions.; P. 1 (executive summary, introduction): The authors may wish to update this section to reflect the latest VA Suicide Data Report (reference 2), which was released in late 2020.; P. 1, lines 26-27 discusses the potential import of community-based approaches for reducing suicide among non-VHA Veterans, which appears to have been an important factor for the current undertaking. Briefly revisiting this in the Conclusion section may thus be useful.; P. 3, lines 11-12: Suggest stating the rationale for excluding studies on safe reporting and messaging about suicide (since this can be community-based or population-based).; P. 16: I agree with the decision to focus on suicide attempts and deaths, but readers might be interested in understanding why suicidal ideation was not an outcome of interest for KQ1.; P. 27, line 16: Minor point - does “contract” here refer to a “no suicide contract”? If so, it would be worth specifying that, as these have actually been shown to be ineffective and potentially harmful.; The current findings regarding multi-component interventions are particularly important given recent community-based initiatives in the U.S., such as the Mayor’s and Governor’s Challenges.; It may be worth noting some of the inherent challenges to studying the effectiveness of community-based interventions for suicide, such as low base rates of suicide and ethical considerations. | We added rationale about categorizing interventions as Organizational Policies and Culture. Per the CDC framework, comprehensive suicide prevention programs targeting “closed communities” such as a workplace or military were categorized under Organizational Policies and Culture, acknowledging that these programs often were multi-component. Thus, the setting influenced how we categorized them.; The SEYLE trial in European high schools had 4 different arms (3 intervention arms and 1 control arm). This allowed us to analyze the specific effects of each intervention.; We revised the introduction to use the 2020 National Veteran Suicide Prevention Annual Report when citing statistics.; We re-visited the idea that community approaches are potentially important for reducing suicide among non-VHA Veterans in the discussion.; We added rationale why we excluded safe reporting and messaging about suicide. That intervention is a part of the CDC strategy of “Lessen harms and prevent future risk.” These interventions take place after a suicide has occurred. This was not the focus of our review.; We added rationale for excluding suicide ideation. A 2016 publication by Klonsky et al. in Annual Review of Clinical Psychology stipulates that “the progression from ideation to suicide attempts are distinct phenomena with distinct explanations and predictors.”; The point about a “no suicide contract” is well-acknowledged. However, the primary study does not further specify what they mean by “contract.”; We added to the discussion that since suicides are rare, it is important for future studies to have adequate follow-up and sample sizes.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | The authors do not make it clear why stigma related to suicide 1 of the outcome measures. I would suggest the addition of some introductory material on why this is important.; Given the timeframe of the review, earlier studies of strategies like the Columbia Suicide Screening Scale might be missed, A brief review of findings from studies before 2010 might be useful for the reader.; p. 22- SA, SD not included as abbreviations; p. 41- Garrett Lee Smith papers are most likely gatekeeper training and not coping and problem solving | Stigma associated with suicide can have negative effects. As expressed by a Centre for Suicide Prevention in Canada, “Many victims suffer from very real psychological scars inflicted by the hurt and shame of attempting suicide or knowing someone who has died by suicide” (accessed at: https://www.suicideinfo.ca/resource/suicideandstigma/ on February 1^st^, 2021). We posited that an unintended consequence of any suicide prevention intervention could be an increase in suicide-related stigma. After reviewing the literature, we did not find evidence of that.; We summarized findings from a prior ESP Report about suicide prevention that was published in 2009. This helps inform readers about findings before our search date.; Abbreviations for SD and SA are placed as footnotes under Table 1 and 3.; We categorized the Garrett Lee Smith program as gatekeeper training.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | This represents a lot of work and an excellent compilation and synthesis. Four comments presented in order of priority:; Tables 1 and 3 look identical.; In the Discussion, you bring up that “the methodological quality on the effectiveness of suicide prevention strategies is limited.” It would be helpful to discuss why that might be the case. What would it take to actually have a community-based intervention that would be of high methodological quality? For things like a public awareness campaign, it may be very hard to think of a feasible and fundable way design a study that would meet such criteria. Similarly, the Future Research section suggests “using RCT trial designs” but for many community-based intervention strategies, I’m not sure that a RCT design can (or even should) be used.; No “peer norm” interventions were found. I wanted to confirm if you checked that the socio-emotional interventions did not include a “peer norm” component. In particular, the Signs of Suicide (US) intervention involves discussion of peer interaction so I’m wondering if this was part of it.; Fine to mention the caveat that the Australian intervention costs were likely in Australian dollars, but can you report the costs in USD based on that assumption? | Tables 1 and 3 are the same. The executive summary is a stand-alone feature of the report.; We revised the “Future Research” section to provide realistic suggestions. RCTs may not be feasible for all community or population-based interventions. However, RCTs in organizational workplaces, schools, or other closed communities could be conducted (example: SEYLE trial in European high schools). In the absence of RCTs, observational studies with concurrent control groups, adequate adjustment for confounding, large sample sizes, and adequate follow-up should be conducted.; We categorized the interventions according to their primary approach. The Signs of Suicide program consisted of a video and guided discussion. The aim was to increase knowledge and improve attitudes, encourage help-seeking, reduce stigma, engage parents and school staff as partners in prevention, and encourage schools to develop partnerships to support mental health. We categorized this as a social-emotional learning program.; We left the cost in question in Australian dollars as this was the context of the study.

CDC=Centers for Disease Control and Prevention; ESP=Evidence Synthesis Program; KQ=Key Question; RCT=Randomized Controlled Trial; SEYLE=Saving and Empowering Young Lives in Europe; SOS=Signs of Suicide; US=United States; USD=United States dollar; VA=Department of Veterans Affairs; VHA=Veterans Health Administration