# APPENDIX 5 DATA ABSTRACTION TABLES AND RISK OF BIAS ASSESSMENTS

Appendix Table 5-1 Housing Stabilization: Study Characteristics

Author, Year; Country; Study Design; Intervention Type; Setting; Funding; Risk of Bias | Inclusion/Exclusion Criteria | Intervention; Comparator; Study Period; Length of Follow-up | Demographics
Montgomery 2020^12^; Country: US; Study Design: Observational with concurrent control; Intervention Type: Housing stabilization; Setting: Military; Funding: US government; Risk of Bias: Medium | Inclusion: Veterans screened positive for current or imminent risk of housing instability at least once using the VHA’s 2-question Homelessness Screening Clinical Reminder (HSC), defined as responded negatively to the question, ‘In the past 2 months, have you been living in stable housing that you own, rent, or stay in as part of a household?’ or positively to the question, ‘Are you worried or concerned that in the next 2 months you may NOT have stable housing that you own, rent, or stay in as part of a household?’; Exclusion: NR | Intervention: Received ≥1 VHA Homeless Program services (n=93,135) Specific programs included: (1) completing an in-depth assessment for VHA Homeless Programs; (2) Domiciliary Care for Homeless Veterans and Compensated Work Therapy with transitional housing; (3) emergency housing services through the healthcare for Homeless Veterans and Safe Haven programs; (4) rapid rehousing and homelessness prevention through Supportive Services for Veteran Families; (5) permanent supportive housing through US Department of Housing and Urban Development-VA Supportive Housing; and (6) transitional housing through the Grant and Per Diem program.; Comparator: Received no VHA Homeless Program services (n=76,086); Study period: October 1, 2012 and September 30, 2016; Length of follow-up: 4 years | N= 169,221; Age (years, mean): Int. 50.3 vs Com. 52.8; P<.05; Gender (% male):; Int. 89.2 vs Com.90; P<.05; Race (%):; White: Int. 55.7 vs, Com. 65.9; P<.05; Black: Int. 34.7 vs, Com. 23.1; P<.05; Military status:100% veterans; Housing status: 100% “housing instability”; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR

Com=Comparator; Int=intervention; VHA=Veterans Health Administration

Appendix Table 5-2 Housing Stabilization: Risk of Bias – Non-RCTs^*^

Author, Year | Did the study include all eligible participants or were the participants a representative sample from the population of interest? | Were the participants included in any comparison similar? | Were the participants included in any comparisons receiving similar treatment/ care, other than the exposure or intervention of interest? | Was the control group concurrent? | For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/ exposure? | Was follow-up complete? | Was completeness of follow-up similar for study groups? | Were the outcomes of participants included in any comparisons measured in the same way? | Were suicide deaths and/or attempts measured in a reliable way? | Were other eligible outcomes measured in a reliable way? | Did the study adjust for confounding variables? | Overall Risk of Bias
Montgomery 2020^12^ | Yes | No | Unclear | Yes | NA | Yes | Yes | Yes | Yes | NA | Yes | Medium

* Modification of the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies

NA=not applicable; RCT=randomized controlled trial

Appendix Table 5-3 Housing Stabilization: Suicide Deaths and Attempts from Non-RCTs with Concurrent Control

Author, Year Study Design | Suicide Deaths | | | | | Suicide Attempts
Author, Year Study Design | Intervention Group | | Control Group | | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post; Intervention vs Control
Author, Year Study Design | Pre | Post | Pre | Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post; Intervention vs Control
Montgomery 2020^12^; Observational with concurrent control | | 0.2%; (157/93,135) | | 0.2%; (140/76,086) | P=.45; Any VHA Homeless Program; Use; aHR^*^; 0.79 (95% CI 0.62 to 1.01); With each additional VHA; Homeless; Program accessed; aHR^**^; 0.81 (95% CI 0.73 to 0.89); Accessed 1 VHA; Homeless; Program; aHR^†^; 0.98 (95% CI 0.74 to 1.29); Accessed 2 VHA; Homeless; Programs; aHR^†^; 0.91 (95% CI 0.65 to 1.28); Accessed 3 VHA; Homeless; Programs; aHR^†^; 0.62 (95% CI 0.40 to 0.96); Accessed ≥4 VHA; Homeless; Programs; aHR^†^; 0.22 (95% CI 0.11 to 0.46) | | 6.0%; (5628/93,135) | | 2.1%; (1594/76,086) | P<.05; Calculated RD; 4% (95% CI 3.8 to 4.1)

aHR=adjusted hazard ratio; CI=confidence interval; RD=risk difference; VHA=Veterans Health Administration

* Model 1 - includes age, sex, race, Hispanic ethnicity, MST, history of suicide ideation, history of suicide attempt, ever diagnosed with depression, weighted Elixhauser medical comorbidity, Enrolment Priority Group and whether the Veteran had any VHA Homeless Program use

** Model 2 - includes age, sex, race, Hispanic ethnicity, MST, history of suicide ideation, history of suicide attempt, ever diagnosed with depression, weighted Elixhauser medical comorbidity, Enrolment Priority Group and the number of VHA Homeless Program used as a continuous variable

† Model 3 includes age, sex, race, Hispanic ethnicity, MST, history of suicide ideation, history of suicide attempt, ever diagnosed with depression, weighted Elixhauser medical comorbidity, Enrolment Priority Group and a categorical measure for whether the Veteran used 0, 1, 2, 3, or 4+ VHA Homeless Programs.

Appendix Table 5-4 Housing Stabilization: Secondary Outcomes

Author, Year; Study Design | Stigma Towards Suicide | Caregiver Burden | Cost | Substitution (Alternative Method)
Montgomery 2020^12^; Observational with concurrent control | NR | NR | NR | NR

NR=not reported

Appendix Table 5-5 Means Restriction: Study Characteristics

Author, Year; Country; Study Design; Intervention Type; Setting; Funding; Risk of Bias | Inclusion/Exclusion Criteria | Intervention; Comparator; Study Period; Length of Follow-up | Demographics
Yip 2010^13^; Country: Hong Kong; Study Design: Observational with concurrent control; Intervention Type: Means restriction (charcoal restriction); Setting: General community; Funding: Government; Risk of Bias: Low | Inclusion: Two geographically adjacent districts in Hong Kong with similar demographic and socioeconomic characteristics. Tuen Mun was the intervention region and Yuen Long was the control region.; Exclusion: None | Intervention: Access to charcoal was limited by removing all barbecue charcoal packs from the open shelves of major retail chains. Customers were required to ask a shop assistant for a pack, which the assistant would then retrieve from a locked container; Comparator: Charcoal packs were displayed as usual; Study period: July 2005 to June 2007; Length of follow-up: 1 year pre- and post-intervention periods | [underlined: Intervention]; N= 502,000 people in Tuen Mun; Age (years, mean): 8.8% 65+ years; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status (% in public rental housing): 34.9%; Socioeconomic status (median household income in Hong Kong $):; 15,000; Mental health diagnoses: NR; Prior suicide behavior: NR; [underlined: Control]; N= 534,000 people in Yuen Long; Age (years, mean): 8.3% 65+ years; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status (% in public rental housing): 35.1%; Socioeconomic status (median household income in Hong Kong $):; 14,810; Mental health diagnoses: NR; Prior suicide behavior: NR
Chen 2015^14^; Country: Taiwan; Study Design: Observational with concurrent control; Intervention Type: Means restriction (charcoal restriction); Setting: General community; Funding: Government and University; Risk of Bias: Medium | Inclusion: Three metropolitan cities in Taiwan that are comparable in terms of level of urbanization and access to retail stores. New Taipei City was the intervention site and Taipei City and Kaohsiung City were control sites.; Exclusion: None | Intervention: New Taipei City required that all charcoal be removed from open shelves of retail stores. Customers purchasing charcoal must ask a shop assistant, who would then retrieve charcoal from a locked container.; Comparator: No intervention in Taipei City and Kaohsiung City; Study period: January 1, 2009 to December 31, 2013; Length of follow-up: 40-months pre- and 20-months post-intervention | [underlined: Intervention]; N= 3.9 million people in New Taipei City; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR; [underlined: Control]; N= 2.7 million people in Taipei City;; 2.7 million people in Kaohsiung City; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR
Jo 2019^15^; Country: South Korea; Study Design: Pre-post observational with no concurrent control; Intervention Type: Means restriction (charcoal restriction); Setting: General community; Funding: Government; Risk of Bias: Medium | Inclusion: Data on suicides and suicides by charcoal burning in Gyeonggi Province from 2000 to 2016, released by the National Statistical Office.; Exclusion: None | Intervention: Shops participating in the program changed the way they sold charcoal: they were kept out of sight, not on display, and they are taken out only when customers request them. The campaign allows sellers to ask about the use of charcoal.; Comparator: Pre-intervention; Study period: 2000 to 2016. During this time, a nation-wide prevention campaign was also ongoing.; Length of follow-up: 2 years. The program started in 2014. It expanded from 1 district in 2014 to 10 districts in 2015 and later to 28 in 2016. | N=about 13 million people in Gyeonggi Province; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Sinyor 2017^16^ (longer-term follow-up); Sinyor 2010^17^ (shorter-term follow-up); Country: Canada; Study Design: Observational with concurrent control; Intervention Type: Means restriction (barrier at bridge); Setting: Suicide hotspot; Funding: Foundation and University; Risk of Bias: Low | Inclusion: Records at the chief coroner’s office of Ontario covering all suicides in Ontario from January 1, 1993 to December 31, 2014.; Exclusion: None | Intervention: Barrier was erected at Bloor Street Viaduct bridge in Toronto. The barrier is about 5 meters high and consists of thousands of thin steel rods spaced closely together and supported externally by an angled steel frame.; Comparator: a) pre-intervention and b) compared with suicides at other bridges; Study period: January 1, 1993 to December 31, 2014; Length of follow-up: 11 years pre- and post-intervention period. | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Law 2014^19^; Country: Australia; Study Design: Observational with concurrent control; Intervention Type: Means restriction (barrier at bridge); Setting: Suicide hotspot; Funding: Government; Risk of Bias: Medium | Inclusion: The location of suicide being in the Greater Brisbane Region or Statistical Area Level 4:301-305 and cause of death by either jumping from high place or drowning.; Exclusion: None | Intervention: Fencing barriers about 3.3 meters high along the sidewalk of the Gateway Bridge. After the new duplication bridge was built in 2010, the barrier was replaced with a similar 1 with a height of 3.6 meters on the original bridge.; Comparator: a) pre-intervention at Gateway Bridge; b) concurrent control at Story Bridge with no physical barriers; Study period: 1990 to 2012; Length of follow-up: 4-year pre- and 19-year post-intervention period | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Perron 2013^18^; Country: Canada; Study Design: Observational with concurrent control; Intervention Type: Means restriction (barrier at bridge); Setting: Suicide hotspots; Funding: NR; Risk of Bias: Medium | Inclusion: Suicide deaths among Quebec residents from the data banks of the chief coroner’s office.; Exclusion: Suicides (n=593) occurring during July to December 2004 when the barrier was under construction. | Intervention: Barrier on Jacques-Cartier Bridge in Québec, Canada; Comparator: a) pre-intervention; b) other jump sites nearby excluding Jacques-Cartier Bridge; Study period: Data collected from 1990 to December 31, 2009; Length of follow-up: 14.5 year pre- and 5-year post-intervention period | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Hemmer 2017^20^; Country: Switzerland; Study Design: Pre-post observational with no concurrent control; Intervention Type: Means restriction (barriers or safety nets at jump sites); Setting: Suicide hotspots; Funding: Government and a Psychiatric Hospital; Risk of Bias: Medium | Inclusion: All jump sites in Switzerland with at least 0.5 suicides on average per year during any period of 10 years within the whole study period. From the 31 identified hotspots, 15 jump locations were included in the analysis.; Exclusion: Jump sites with poor-quality data and not being within the study time period. | Intervention: Structural interventions at jumping sites. Eleven jump sites were secured by barriers and 4 by safety nets. Of the 15 jump sites, 9 sites also had a help sign.; Comparator: a) pre-intervention and b) barriers vs safety nets; Study period: 1990-2013; Length of follow-up: pre-intervention mean duration of 178.6 months and post-intervention of 73.4 months | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Law 2011^21^; Country: Hong Kong; Study Design: Observational with concurrent control; Intervention Type: Means restriction (platform screen doors at railway stations); Setting: Suicide hotspot; Funding: NR; Risk of Bias: Medium | Inclusion: Information related to falls onto railway tracks from the Safety Office of the Mass Transit Railway Corporation Limited through the Transport and Housing Bureau of the Hong Kong Special Administration Region government. The patronage figures, the cost and the schedule of the platform screen door installation were made available from the same agency. Information on per capita gross domestic product was made available from the Census and Statistics Department of Hong Kong.; Exclusion: None | Intervention: Platform screen doors at railway stations operated by Mass Transit Railway Corporation Limited - intended to restrict passengers’ access to railway tracks; Comparator: railway stations without platform screen doors at stations operated by Kowloon-Canton Railway Corporation; Study period: 1997 to 2007; Length of follow-up: ~5 years. Most of the platforms were sealed in 2002 and the whole project done in 2005 | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Chung 2016^22^; Country: South Korea; Study Design: Pre-post observational with no concurrent control; Intervention Type: Means restriction (platform screen doors at railway stations); Setting: Suicide hotspots; Funding: Government and Foundation; Risk of Bias: Medium | Inclusion: Data on individual suicide cases that occurred between 2003 and 2012 at subway stations operated by Seoul Metro (121 total stations), which operates 50% of the subway stations in Seoul.; Exclusion: None | Intervention: Platform screen doors installed at subway stations. 119 stations had full-height platform screen doors that extended completely or almost completely to the ceiling. Two stations had half-height platform screen doors (measured at 1.65 meters).; Comparator: Subway stations prior to installing platform screen doors; Study period: 2003 to 2012; Length of follow-up: 3 to 7 years. Screen doors started to be installed in 2005 and completed in 2009. | N= NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Ueda 2015^23^; Country: Japan; Study Design: Observational with concurrent control; Intervention Type: Means restriction (platform screen doors at railway stations); Setting: Suicide hotspots; Funding: Government, Foundation, and life insurance company; Risk of Bias: Low | Inclusion: Data on suicide and accidents obtained from a major railway company in the Tokyo metropolitan area. Only incidents that occurred at stations were included in the analysis.; Exclusion: Railway stations that started operating in 2008 (8.7% of all stations) because their accident and suicide records were available only for a subset of years. | Intervention: Platform screen doors at train stations. When the study started, 19 stations had platform screen doors. They were installed at 71 stations by end of study. Among them, 73.24% were half-height platform screen doors.; Comparator: Rail stations without platform screen doors and prior to them being installed. At the end of study, 97 stations did not have platform screen doors.; Study period: Data collected from April 2004 to March 2014; Length of follow-up: Varied; platform screen doors were gradually installed during study period | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Matsubayashi 2013^24^; Matsubayashi 2014^25^; Ichikawa 2014^26^; The 3 articles used datasets that overlapped. To avoid double-counting, we mapped them to the same study.; Country: Japan; Study Design: Observational with concurrent control; Intervention Type: Means restriction (blue lights at railway platforms); Setting: Suicide hotspots; Funding: Government, Foundation; Risk of Bias: Medium | Inclusion:; Matsubayashi 2013 and 2014:; Data from 71 rail stations provided by a rail company.; Ichikawa 2014:; Data compiled by the Japanese Ministry of Land, Infrastructure, Transport and Tourism; Exclusion:; Matsubayashi 2013 and 2014:; NR; Ichikawa 2014:; Suicide attempts within the train or by jumping out of the train | Intervention: Installation of blue light- emitting-diode lamps on railway platforms and at railway crossings as a method of deterring suicides; Comparator: Railway stations without blue lights installed; Study period:; Matsubayashi 2013: 2000-2010; Matsubayashi 2014: 2000-2013; Ichikawa 2014: 2002-2012; Length of follow-up:; Matsubayashi 2013: 1-3 years from installation to end of data collection; Matsubayashi 2014: 1-6 years from installation to end of data collection; Note: follow-up varied by platform as blue lights were installed over time. They started to be installed in 2008. | N=NR; Age (years, mean):NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR

NR=not reported

Appendix Table 5-6 Means Restriction: Risk of Bias – Non-RCTs^*^

Author, Year | Did the study include all eligible participants or were the participants a representative sample from the population of interest? | Were the participants included in any comparison similar? | Were the participants included in any comparisons receiving similar treatment/ care, other than the exposure or intervention of interest? | Was the control group concurrent? | For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/exposure? | Was follow-up complete? | Was completeness of follow-up similar for study groups? | Were the outcomes of participants included in any comparisons measured in the same way? | Were suicide deaths and/or attempts measured in a reliable way? | Were other eligible outcomes measured in a reliable way? | Did the study adjust for confounding variables? | Overall Risk of Bias
Yip 2010^13^ | Yes | Yes | Unclear | Yes | NA | NA | NA | Yes | Yes | NA | Yes | Low
Chen 2015^14^ | Yes | Yes | Unclear | Yes | No | NA | NA | Yes | Yes | NA | No | Medium
Jo 2019^15^ | Yes | Yes | Unclear | No | Yes | NA | NA | Yes | Yes | NA | No | Medium
Sinyor 2017^16^; Sinyor 2010^17^ | Yes | Unclear | Unclear | Yes | Yes | NA | NA | Yes | Yes | NA | Yes; (Sinyor 2017); No; (Sinyor 2010) | Low
Law 2014^19^ | Yes | Unclear | Unclear | Yes | No | NA | NA | Yes | Yes | Unclear (cost) | Unclear | Medium
Perron 2013^18^ | Yes | Unclear | Unclear | Yes | No | NA | NA | Yes | Yes | NA | No | Medium
Hemmer 2017^20^ | Yes | Unclear | Unclear | No | No | NA | NA | Unclear | Yes | NA | No | Medium
Saeheim 2017^73^ | Yes | Unclear | Unclear | No | No | NA | NA | Yes | Yes | NA | No | High
Law 2011^21^ | Yes | Unclear | Unclear | Yes | No | NA | NA | Yes | Yes | Yes (cost) | Yes | Medium
Chung 2016^22^ | Yes | Unclear | Unclear | No | Yes | NA | NA | Unclear | Unclear | Unclear (cost) | Yes | Medium
Ueda, 2015^23^ | Yes | Unclear | Unclear | Yes | Yes | NA | NA | Yes | Yes | NA | Yes | Low
Matsubayashi 2013^24^; Matsubayashi 2014^25^; Ichikawa 2014^26^ | Yes | Unclear | Unclear | Yes | Yes | No | NA | NA | Yes | NA | NA | Medium

* Modification of the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies

NA=not applicable; RCT=randomized controlled trial

Appendix Table 5-7 Means Restriction: Suicide Deaths and Attempts from Non-RCTs with Concurrent Control

Author, Year; Study; Design; Intervention; Details | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study; Design; Intervention; Details | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study; Design; Intervention; Details | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Yip 2010^13^; Observational with concurrent control; Charcoal restriction | charcoal suicides; 1 year:; 21 suicides; 4.3 per 100,000 | charcoal suicides; 1 year:; 10 suicides; 2.0 per 100,000 | charcoal suicides; 1 year:; 16 suicides; 3.0 per 100,000 | charcoal suicides; 1 year:; 23 suicides; 4.3 per 100,000 | [underlined: Intervention]; Charcoal suicides; P<.05 pre vs post | charcoal suicides; −66.9% adjusted difference on percentage change; P=.03 | NR | NR | NR | NR | NR | NR
Yip 2010^13^; Observational with concurrent control; Charcoal restriction | Men; 1 year:; 16 suicides; 6.6 per 100,000 | Men; 1 year:; 7 suicides; 2.9 per 100,000 | Men; 1 year:; 10 suicides; 3.9 per 100,000 | Men; 1 year:; 16 suicides; 6.2 per 100,000 | [underlined: Intervention]; Charcoal suicides; P<.05 pre vs post | Men; −72.7% adjusted difference on percent change; P=.03 | NR | NR | NR | NR | NR | NR
Yip 2010^13^; Observational with concurrent control; Charcoal restriction | Women; 1 year:; 5 suicides; 2.0 per 100,000 | Women; 1 year:; 3 suicides; 1.2 per 100,000 | Women; 1 year:; 6 suicides; 2.2 per 100,000 | Women; 1 year:; 7 suicides; 2.6 per 100,000 | [underlined: Intervention]; Charcoal suicides; P<.05 pre vs post | Women; −48.6% adjusted difference on percent change; P=.47 | NR | NR | NR | NR | NR | NR
Chen 2015^14^; Observational with concurrent control; Charcoal restriction | charcoal suicides; N=808; 6.2 per 100,000 | charcoal suicides; N=256; 3.9 per 100,000 | charcoal suicides (Taipei City); N=305; 3.5 per 100,000 | charcoal suicides (Taipei City); N=111; 2.5 per 100,000 | Charcoal suicides; [underlined: New Taipei City]; decrease of 37% (95% CI 17% to 50%) pre vs post; Decrease of 30% (95% CI 14% to 44%) relative to Kaohsiung City; Time series regression P=.001; [underlined: Taipei City]; Time series regression P=.10; [underlined: Kaohsiung City]; Time series regression P=.85; Subgroups; Numerical decreases in charcoal suicides in New Taipei City were found in all age and sex groups, except men 65+ years old | | NR | NR | NR | NR | NR | NR
Chen 2015^14^; Observational with concurrent control; Charcoal restriction | | | charcoal suicides (Kaohsiung City); N=490; 5.3 per 100,000 | charcoal suicides (Kaohsiung City); N=219; 4.7 per 100,000 | | | NR | NR | NR | NR | NR | NR
Sinyor 2017^16^; Sinyor 2010^17^; Observational with concurrent control; Barrier at bridge | Bloor Street Viaduct; 1993-2003:; 9.5 suicides observed per year | Bloor Street Viaduct; 2004-2014:; 0.1 suicides observed per year | Other bridges:; 1993-2003:; 10.1 suicides observed per year | Other bridges:; 2004-2014:; 11.0 suicides observed per year | [underlined: Intervention]; Bloor Street Viaduct; 2004-2014:; IRR= 0.009 (95% CI, 0.0005 to 0.19); 2003-2007:; IRR= 0.05 (95% CI, 0.01 to 0.31); [underlined: Control]; Other bridges; 2004-2014:; IRR= 1.03 (95% CI, 0.76 to 1.40); 2003-2007:; IRR= 1.64 (95% CI, 1.13 to 2.39) | NR | NR | NR | NR | NR | NR | NR
Sinyor 2017^16^; Sinyor 2010^17^; Observational with concurrent control; Barrier at bridge | | 2003-2007:; 0 suicides observed per year | | 2003-2007:; 15.3 suicides observed per year | | NR | NR | NR | NR | NR | NR | NR
Law 2014^19^; Observational with concurrent control; Barrier at bridge | Gateway Bridge; 1990-1993:; 22 suicides; 0.673 suicides per 100,000 persons | Gateway Bridge; 1994-2012:; 16 suicides; 0.084 suicides per 100,000 persons | Story Bridge; 1990-1993:; 15 suicides; 0.459 suicides per 100,000 persons | Story Bridge; 1994-2012:; 73 suicides; 0.382 suicides per 100,000 persons | [underlined: Intervention]; Gateway Bridge; 1994-2012 vs pre:; −87.5% change P=.000; 1994-1997 vs pre:; −53.0% change P=.041; [underlined: Control]; Story Bridge; 1994-2012 vs pre:; −16.7% change P=.520; 1994-1997 vs pre:; 6.6% change P=.857 | NR | NR | NR | NR | NR | NR | NR
Law 2014^19^; Observational with concurrent control; Barrier at bridge | | 1994-1997:; 11 suicides; 0.316 suicides per 100,000 persons | | 1994-1997:; 17 suicides; 0.489 suicides per 100,000 persons | | NR | NR | NR | NR | NR | NR | NR
Perron 2013^18^; Observational with concurrent control; Barrier at bridge | Jacques-Cartier; 1990-2004:; 0.324 suicides per 100,000 persons; 10.0 annual suicides | Jacques-Cartier; 2005-2009:; 0.079 suicides per 100,000 persons; 2.6 annual suicides | Other jumping sites; 1990-2004:; 0.844 suicides per 100,000 persons; 26.1 annual suicides | Other jumping sites; 2005-2009:; 0.687 suicides per 100,000 persons; 22.5 annual suicides | [underlined: Intervention]; Jacques-Cartier; IRR= 0.24 (95% CI, 0.13 to 0.43); [underlined: Control]; Other jumping sites; IRR= 0.82 (95% CI, 0.66 to 1.01) | NR | NR | NR | NR | NR | NR | NR
Law 2011^21^; Observational with concurrent control; Platform screen door at railway stations | Mass Transit; 1997-2001:; 38 suicides | Mass Transit; 2003-2007:; 8 suicides | Kowloon-Canton; 1997-2001:; 13 suicides | Kowloon-Canton; 2003-2007:; 15 suicides | [underlined: Intervention]; Mass Transit; −80.6% 5-year average percent change; P<.0001 vs pre; [underlined: Control]; Kowloon-Canton; 8.8% 5-year average percent change; P=.824 vs pre | NR | Mass Transit; 1997-2001:; 33 non-fatal suicide falls | Mass Transit; 2003-2007:; 17 non-fatal suicide falls | Kowloon-Canton; 1997-2001:; 11 non-fatal suicide falls | Kowloon-Canton; 2003-2007:; 12 non-fatal suicide falls | [underlined: Intervention]; Mass Transit; −52.6% 5-year average percent change; P=.0126; [underlined: Control]; Kowloon-Canton; 1.5% 5-year average percent change; P=.9713 | NR
Ueda 2015^23^; Observational with concurrent control; Platform screen door at railway stations | The study reported the composite outcome fatal and non-fatal suicides. Based on the reported data, we calculated that 2 suicide deaths occurred at stations with platform screen doors over 5417 station-months and 57 suicide deaths occurred at stations without platform screen doors over 14743 station-months. We did not prioritize this study in the write-up due to the difficulty of interpreting this result. This study is included in the counts in Table 2. | | | | | | The study reported the composite outcome fatal and non-fatal suicides. Based on the reported data, we calculated 5 non-fatal suicide attempts at stations with platform screen doors over 5417 station-months and 80 non-fatal suicide attempts at stations without platform screen doors over 14743 station-months. We did not prioritize this study in the write-up due to the difficulty of interpreting this result. This study is included in the counts in Table 2.
Matsubayashi 2013^24^; Matsubayashi 2014^25^; Ichikawa, 2014^26^; Observational with concurrent control; Blue lights at railway stations | 2014 paper:; 0.44 suicides/year | 2014 paper:; 0.19 suicides/year | 2014 paper:; Suicides/year ranged from 0.23-0.28 at nearby stations (1 to 5 stations away) | 2014 paper:; Suicides/year ranged from 0.25-0.28 at nearby stations (1 to 5 stations away) | 2014 paper:; [underlined: Intervention]; IRR= 0.26 (95% CI, 0.13 to 0.52); 2013 paper:; [underlined: Intervention]; IRR= 0.17 (95% CI, 0.03 to 0.87) | NR | Ichikawa 2014; The authors analyzed the location and time of day when suicide attempts occurred at railway stations. This gives an estimate of how many suicide attempts are potentially preventable by blue lights (meaning the proportion of attempts that occurred at a time and place where the blue lights could be seen). This analysis does not report the effects of blue lights on attempts.; Among suicide attempts at railways stations:; 43% occurred within stations premises,; 43% were at night, and; 14% fell in both categories

CI=confidence interval; IRR=incident rate ratio; NR=not reported; RCT=randomized controlled trial

Appendix Table 5-8 Means Restriction: Suicides Deaths and Attempts from Non-RCTs with No Concurrent Control

Author, Year; Study Design; Intervention Details | Suicide Deaths | | | Suicide Attempts
Author, Year; Study Design; Intervention Details | Pre-Intervention | Post-Intervention | Pre vs Post Comparison | Pre-Intervention | Post-Intervention | Pre vs Post Comparison
Jo 2019^15^; Pre-post observational with no concurrent control; Charcoal restriction | charcoal suicides; 2012: 294 suicides; 2013: 286 suicides; 2014: 536 suicides | charcoal suicides; 2015: 514 suicides; 2016: 433 suicides | charcoal suicides; Multivariate time series; P=.029 | NR | NR | NR
Hemmer 2017^20^; Pre-post observational with no concurrent control; Barrier and safety nets at bridges | all 15 jump sites; 1.47 suicides/year | all 15 jump sites; 0.41 suicides/year | all 15 jump sites; RR=0.30 (95% CI 0.17 to 0.44); 71.7% prevention | NR | NR | NR
Hemmer 2017^20^; Pre-post observational with no concurrent control; Barrier and safety nets at bridges | structural barriers; 1.61 suicides/year | structural barriers; 0.51 suicides/year | structural barriers; RR=0.34 (95% CI 0.18 to 0.64); 68.7% prevention | NR | NR | NR
Hemmer 2017^20^; Pre-post observational with no concurrent control; Barrier and safety nets at bridges | safety nets; 1.01 suicides/year | safety nets; 0.23 suicides/year | safety nets; RR=0.21 (95% CI 0.07 to 0.62); 77.1% prevention; No significant difference for safety nets vs barriers | NR | NR | NR
Hemmer 2017^20^; Pre-post observational with no concurrent control; Barrier and safety nets at bridges | completed safety measures; 1.62 suicides/year | completed safety measures; 0.57 suicides/year | completed safety measures; RR=0.18 (95% CI 0.10 to 0.44); 82.0% prevention | NR | NR | NR
Chung 2016^22^; Pre-post observational with no concurrent control; Platform screen doors at railway stations | suicides at subway stations; 132 suicides over 8769 station-months | suicides at subway stations; 3 total suicides over 5751 station-months; All 3 suicides were at stations with half-height platform screen doors (not full-height screen doors); For 3 years with complete installation (2010-2012), there was 1 suicide | suicides at subway stations; IRR=0.11 (95% CI 0.03 to 0.43) | NR | NR | NR

CI=confidence interval; IRR=incident rate ratio; NR=not reported; RCT=randomized controlled trial; RR=rate ratio

Appendix Table 5-9 Means Restriction: Secondary Outcomes

Author, Year; Study Design; Intervention Details | Stigma Towards Suicide | Caregiver Burden | Cost | Substitution (Alternative Method)
Yip 2010^13^; Observational with concurrent control; Charcoal restriction | NR | NR | NR | Intervention region: other methods; Pre-intervention:; 67 suicides; 13.6 per 100,000; 1-year follow-up:; 50 suicides; 10.2 per 100,000; Men only-; Pre-intervention:; 35 suicides; 14.5 per 100,000; 1-year follow-up:; 26 suicides; 10.8 per 100,000; Women only-; Pre-intervention:; 32 suicides; 12.8 per 100,000; 1-year follow-up:; 24 suicides; 9.6 per 100,000; Control region: other methods; Pre-intervention:; 51 suicides; 9.6 per 100,000; 1-year follow-up:; 43 suicides; 8.1 per 100,000; Men only-; Pre-intervention:; 28 suicides; 10.8 per 100,000; 1-year follow-up:; 23 suicides; 8.9 per 100,000; Women only-; Pre-intervention:; 23 suicides; 8.5 per 100,000; 1-year follow-up:; 20 suicides; 7.4 per 100,000
Chen 2015^14^; Observational with concurrent control; Charcoal restriction | NR | NR | NR | Intervention region: other methods; Pre-intervention:; N=1598; 12.3 per 100,000; Follow-up:; N=783; 11.9 per 100,000; Time series regression P=.68; Control region (Taipei City): other methods; Pre-intervention:; N=945; 10.8 per 100,000; Follow-up:; N=471; 10.6 per 100,000; Time series regression P=.85; Control region (Kaohsiung City): other methods; Pre-intervention:; N=1381; 14.9 per 100,000; Follow-up:; N=684; 14.8 per 100,000; Time series regression P=.25
Jo 2019^15^; Pre-post observational with no concurrent control; Charcoal restriction | NR | NR | NR | Besides charcoal burning, the only other suicide method that fell more than 0.5% from 2014 was hanging (53.4% to 52.4%)
Sinyor 2017^16^; Sinyor 2010^17^; Observational with concurrent control; Barrier at bridge | NR | NR | NR | Pre-intervention: other methods; 197.7 suicides observed per year; Post-intervention: other methods; From 2004-2014:; 177.5 suicides observed per year; IRR=0.84 (95% CI 0.76 to 0.93); From 2003-2007:; 180.8 suicides observed per year; IRR=0.86 (95% CI 0.74 to 0.99)
Law 2014^19^; Observational with concurrent control; Barrier at bridge | NR | NR | Installation costs; new barriers at the Gateway Bridge in 2010 incurred a direct cost of $2.2 million | NR
Perron 2013^18^; Observational with concurrent control; Barrier at bridge | NR | NR | NR | NR
Hemmer 2017^20^; Pre-post observational with no concurrent control; Barrier and safety nets at jump sites | NR | NR | NR | NR
Law 2011^21^; Observational with concurrent control; Platform screen doors at railway stations | NR | NR | Installation costs; $256.4 million USD according to railway corporation; Estimated $237,748,900 after adjustment of price and discounting; Net costs; Traditional approach: $237,748,900 USD; Modified approach: $229,851,700 USD after accounting for $7,897,200 saved from loss fare revenue; Incremental cost-effectiveness ratios; Traditional approach: 77,874 USD per person-year; Modified approach: 65,354 USD per person-year; Minimal useful life-years to be cost-effective; Traditional approach: 27 years; Modified approach: 21 years | NR
Chung 2016^22^; Pre-post observational with no concurrent control; Platform screen doors at railway stations | NR | NR | Installation costs; 194.06 million USD across 121 stations | NR
Ueda 2015^23^; Observational with concurrent control; Platform screen doors at railway stations | NR | NR | NR | NR
Matsubayashi 2013^24^; Matsubayashi 2014^25^; Ichikawa 2014^26^; Observational with concurrent control; Blue lights at railway stations | NR | NR | NR | NR

CI=confidence interval; IRR=incident rate ratio; NR=not reported; USD=United States Dollar

Appendix Table 5-10 Means Restriction: Strategies to Deliver, Sustain, and Improve the Quality of Intervention^*^

Author, Year; Study Design; Intervention; Details | Strategies to Deliver the Intervention | Strategies to Sustain the Intervention | Strategies to Improve the Quality of the Intervention
Yip 2010^13^; Observational with concurrent control; Charcoal restriction | Two on-site quality checks for compliance (fidelity) over the 1-year intervention period | Need to consider unintended consequences of reduced charcoal sales which may be a deterrent to widespread adoption and dissemination | NR
Chen 2015^14^; Observational with concurrent control; Charcoal restriction | Chain supermarkets were regularly audited for compliance (fidelity) | Authors state future studies will need to engage multiple stakeholder groups (store administrators, store employees and managers, the public) to support this initiative given its inconvenience; Media influence and public awareness may influence results | While not directly linked to the intervention being tested in the study, the authors state that stores also increased use and access to pamphlets/leaflets with education and resources. In addition, store clerks were advised to monitor behaviors of people buying charcoal and provide pamphlets as needed.
Sinyor 2017^16^; Sinyor 2010^17^; Observational with concurrent control; Barrier at bridge | NR | Media influence can potentially help or hurt immediate success of a bridge barrier designed as a suicide prevention strategy | Future study is needed to evaluate the effect of a comprehensive suicide prevention strategy that includes the barrier in addition to education, reduced stigma, and adequate resources for help.
Law 2014^19^; Observational with concurrent control; Barrier at bridge | NR | Authors state more research is needed to evaluate cost-effectiveness to assist policy makers in decisions regarding the installation of barriers | NR
Perron 2013^18^; Observational with concurrent control; Barrier at bridge | NR | NR | Future study is needed to evaluate the effect of a comprehensive suicide prevention strategy that includes the barrier in addition to depression screening and access to treatment
Law 2011^21^; Observational with concurrent control; Platform screen doors at railway stations | NR | The studies evaluated the societal and economic outcomes of barrier placement, which was overall considered cost-effective and relevant to stakeholders; Cost remains a huge barrier when asking railroad companies to extend construction across all lines/stations; Effective resource allocation is an important factor in policy-makers’ decisions; community acceptance (increased fares and wait times), availability of funds, and media influence need to be considered in future studies | NR
Ueda 2015^23^; Observational with concurrent control; Platform screen doors at railway stations | Need to consider station design and costs when deciding to install full versus half height platform screen doors | NR | NR

NR=not reported

* We abstracted this information from studies that found an intervention to be effective (defined as yielding at least low certainty evidence on reducing suicide deaths or attempts).

Appendix Table 5-11 Organizational Policies and Culture: Study Characteristics

Author, Year; Country; Study Design; Intervention Type; Setting; Funding; Risk of Bias | Inclusion/Exclusion Criteria | Intervention; Comparator; Study Period; Length of Follow-up | Demographics
Mishara 2012^27^; Country: Canada; Study Design: Observational with concurrent control; Intervention Type: Organizational Policies and Culture; Setting: workplace (police); Funding: Government; Risk of Bias: Medium | Inclusion: Program was provided to all members of the Montreal police. Data was compared with other police suicides in the Province of Quebec.; Exclusion: None reported | Intervention: Together for Life program for Montreal police; 1) Training for all units (suicide education); 2) Police resources (telephone helpline); 3) Training of supervisors and union representatives (identification of officers at risk; how to provide help); 4) Publicity campaign (“Together for Life”, brochures, posters, internal news articles); Comparator:; 1) Pre-intervention in Montreal police; 2) Police in the rest of Quebec; Study period: 1986-2008; Length of follow-up: 12 years after program and data for 11 years before program | [underlined: Intervention Sites]; N=4178 (Montreal police force as of December 31, 2000); Age (years):; 20-29: 27%; 30-39: 43%; 40-49: 21%; 50-59: 8%; 60+: <1%; Gender (% male): 78; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: 30.5 suicides per 100,000 per year (pre-intervention Montreal police); [underlined: Control Sites]; N=10,131 (police rest of Quebec as of 1986-1996); Age (years): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: 26.0 suicides per 100,000 per year (pre-intervention police rest of Quebec)
Doran 2016^30^; Country: Australia; Study Design: Pre-post observational with no concurrent control; Intervention Type: Organizational Policies and Culture; Setting: Workplace (construction); Funding: NR; Risk of Bias: Medium | Inclusion: Males construction industry workers in New South Wales and Queensland; Exclusion: Women, due to the small numbers of women in the construction industry and consequent confidentiality issues with reporting small sample sizes | Intervention: Mates in Construction program for Australian construction workers; 1) General awareness training – 1 hour training session provided by accredited trainers to construction workers on site; aims are increasing awareness of suicide as a work place health and safety issue, improving knowledge of warning signs, and encouraging workers to seek support; 2) Connector training – 4 hour training session; role of connector is to keep coworkers safe while connecting them to help; 3) Applied suicide intervention skills training – 2-day training course to enable these individuals to identify cases and respond appropriately to calls for help; Sites also receive promotional materials and access to other programs including 24/7 helpline; Comparator: Pre-intervention; Study period:; Queensland: 2003-2012; New South Wales: 2008-2017; Length of follow-up:; Queensland: 5 years; New South Wales: the post data was estimated, not originally collected | N:; Queensland pre: 708,950; Queensland post: 841,425; New South Wales pre: 1,068,500; Age (years, mean): NR; Gender (% male): 100; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Knox 2010^28^; Country: United States; Study Design: Pre-post observational with no concurrent control; Intervention Type: Organizational Policies and Culture; Setting: Military setting; Funding: Government; Risk of Bias: Medium | Inclusion: Quarterly suicide rates for active duty air force population from 1981 through 2007 and forecasted for 2008.; Exclusion: None reported | Intervention: US Air Force Suicide Prevention Program; Leadership involvement; Addressing suicide prevention through professional military education; Guidelines for commanders on use of mental health services; Community preventive services; Community education and training; Investigative intervention policy; Trauma stress response; Integrated Delivery System and Community Action Information Board; Limited Privilege Suicide Prevention Program; Integrated Delivery System Consultation Assessment Tool; Suicide Event Surveillance System; Comparator: Pre-intervention; Study period: 1981-2008; Length of follow-up: 11 years after program. Data for 16 years before | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Shelef 2016^29^; Country: Israel; Study Design: Pre-post observational with no concurrent control; Intervention Type: Organizational policies and culture; Setting: Military settings; Funding: NR; Risk of Bias: Medium | Inclusion: Active duty mandatory service Israeli Defense Forces soldiers that served during the years 1992 to 2012.; Exclusion: Subsection of the population (n=176,287) that does not represent the regular mandatory service Israeli Defense Forces soldiers. | Intervention: Israeli Defense Forces Suicide Prevention Program; Reduce weapon availability; Improve screening and management of suicidal soldiers; Identify specific populations profiled for intervention by employing 2 indices: a) service timeline; b) subgroups with increased risk and gatekeeper groups Reduce stigma through education and integrating Mental Health Officers in army units and increasing availability of Mental Health Officers through the Human Resources Division; Develop a suicide review process; Comparator: Pre-intervention; Study period: 1992-2012; Length of follow-up: 7 years after program. Data for 14 years before | N=1,171,359 active duty mandatory service soldiers; Age (years, mean): 19; Gender (% male): 53.4%; Race (%): NR; Military status: All active duty. 16.9% combat duty; Housing status: NR; Socioeconomic status: 24.0% low, 53.8% average, 22.2% high; Mental health diagnoses: 2.7%; Prior suicide behavior: NR

NR=not reported

Appendix Table 5-12 Organizational Policies and Culture: Risk of Bias – Non-RCTs^*^

Author, Year | Did the study include all eligible participants or were the participants a representative sample from the population of interest? | Were the participants included in any comparison similar? | Were the participants included in any comparisons receiving similar treatment/ care, other than the exposure or intervention of interest? | Was the control group concurrent? | For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/exposure? | Was follow-up complete? | Was completeness of follow-up similar for study groups? | Were the outcomes of participants included in any comparisons measured in the same way? | Were suicide deaths and/or attempts measured in a reliable way? | Were other eligible outcomes measured in a reliable way? | Did the study adjust for confounding variables? | Overall Risk of Bias
Mishara 2012^27^ | Yes | Unclear | Unclear | Yes | Yes | Unclear | Unclear | Yes | Yes | NA | No | Medium
Doran 2016 ^30^ | Yes | Unclear | Unclear | NA | Yes | Yes | Yes | Yes | Unclear | Yes (cost) | No | Medium
Finney 2015^74^ | Yes | Unclear | Unclear | No | Yes | NA | NA | Unclear | Unclear | NA | No | High
Knox 2010^28^ | Yes | Unclear | Yes | NA | Yes | NA | NA | Yes | Yes | NA | No | Medium
Shelef 2016^29^ | Yes | No | NA | NA | Yes | NA | NA | Yes | Yes | NA | Yes | Medium

* Modification of the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies

NA=not applicable; RCT=randomized controlled trial

Appendix Table 5-13 Organizational Policies and Culture: Suicide Deaths and Attempts from Non-RCTs with Concurrent Control

Author, Year; Study Design | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study Design | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study Design | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Mishara 2012^27^; Observational with concurrent control | Montreal police; 11 years before:; 30.5 per 100,000 per year | Montreal police; 12 years after:; 6.4 per 100,000 | Rest of Quebec Police; 11 years before:; 26.0 per 100,000 per year | Rest of Quebec Police; 12 years after:; 29.0 per 100,000 | Montreal police; Change −78.9% (95% CI −93.3 to −33.4); Rest of Quebec Police; Change 11.4% (95% CI −33.3 to 86.2) | Pre:; P=.63 Montreal vs rest of Quebec; Post:; P=.007 Montreal vs rest of Quebec | NR | NR | NR | NR | NR | NR
Mishara 2012^27^; Observational with concurrent control | 14 suicides/4178 people | 4 suicides/5189 people | 29 suicides/10131 people | 32 suicides/9197 people | Montreal police; Change −78.9% (95% CI −93.3 to −33.4); Rest of Quebec Police; Change 11.4% (95% CI −33.3 to 86.2) | Pre:; P=.63 Montreal vs rest of Quebec; Post:; P=.007 Montreal vs rest of Quebec | NR | NR | NR | NR | NR | NR

CI=confidence interval; NR=not reported; RCT=randomized controlled trial

Appendix Table 5-14 Organizational Policies and Culture: Suicides Deaths and Attempts from Non-RCTs with No Concurrent Control

Author, Year; Study Design | Suicide Deaths | | | Suicide Attempts
Author, Year; Study Design | Pre-Intervention | Post-Intervention | Pre vs Post Comparison | Pre-Intervention | Post-Intervention | Pre vs Post Comparison
Doran 2016^30^; Pre-post observational with no concurrent control | Queensland; Rate: 29.20 per 100,000; 207 suicides/ 708,950 people; New South Wales was not extracted for suicide deaths because the post-intervention data was estimated | Queensland; Rate: 26.38 per 100,000; 222 suicides/841,425 people | Queensland; RRR (post/pre rate)= 0.904 (95% CI 0.900 to 0.909); −9.6% change (95% CI −10.0% to −9.1%) | NR | NR | NR
Knox 2010^28^; Pre-post observational with no concurrent control | 1981-1997:; 3.033 suicides per quarter per 100,000 persons | 1997-2008:; 2.387 suicides per quarter per 100,000 persons | −0.646 suicides per quarter per 100,000; P<.01 | NR | NR | NR
Shelef 2016^29^; Pre-post observational with no concurrent control | 1992-2005:; 24.6 suicides/year; 344 total suicides; Females; 4.3 per 100,000 person-year; 24 suicides/364,810 people; Males; 35.6 per 100,000 person-year; 320 suicides/401,297 people | 2006-2012:; 12.7 suicides/year; 89 total suicides; Females; 3.5 per 100,000 person-year; 12 suicides/181,458 people; Males; 16.0 per 100,000 person-year; 77 suicides/223,794 people | HR adjusted=0.42 (95% CI 0.33 to 0.54); Females; HR unadjusted=0.90 (95% CI 0.45 to 1.83); Males; HR adjusted=0.43 (95% CI 0.33-0.55) | NR | NR | NR

CI=confidence interval; HR=hazard ratio; NR=not reported; RCT=randomized controlled trial; RRR=relative risk ratio

Appendix Table 5-15 Organizational Policies and Culture: Secondary Outcomes

Author, Year; Study Design | Stigma Towards Suicide | Caregiver Burden | Cost | Substitution (Alternative Method)
Mishara 2012^27^; Observational with concurrent control | NR | NR | NR | NR
Doran 2016^30^; Pre-post observational with no concurrent control | NR | NR | Cost of Intervention; NR; the model used $800,000 each year (Australian dollars) as cost of the program; Total Cost Savings; Impact of implementing the program in New South Wales was estimated to save $3.66 million (Australian dollars) each year; The benefit-cost ratio was estimated to be 4.6:1 | NR
Knox 2010^28^; Pre-post observational with no concurrent control | NR | NR | NR | NR
Shelef 2016^29^; Pre-post observational with no concurrent control | NR | NR | NR | NR

NR=not reported

Appendix Table 5-16 Organizational Policies and Culture: Strategies to Deliver, Sustain, and Improve the Quality of Intervention^*^

Author, Year; Study Design | Strategies to Deliver the Intervention | Strategies to Sustain the Intervention | Strategies to Improve the Quality of the Intervention
Mishara 2012^27^; Observational with concurrent control | Utilizing peers to deliver the program who share a “common language” | Creating a culture that suicidal behavior is not an acceptable way to deal with a crisis | Stakeholders indicated that the training could be improved and sustained with annual refresher courses, follow-up, or memory aids

* We abstracted this information from studies that found an intervention to be effective (defined as yielding at least low certainty evidence on reducing suicide deaths or attempts).

Appendix Table 5-17 Social-Emotional Learning Programs: Study Characteristics

Author, Year; Country; Study Design; Intervention Type; Setting; Funding; Risk of Bias | Inclusion/Exclusion Criteria | Intervention; Comparator; Study Period; Length of Follow-up | Demographics
Schilling 2016^31^; Country: United States; Study Design: Cluster RCT; Intervention Type: Social-Emotional Learning Program; Setting: High school; Funding: Foundation; Risk of Bias: Medium | Inclusion: 9^th^ grade students at 16 technical high schools in Connecticut; Exclusion: NR | Intervention: High schools assigned to the Signs of Suicide program. Schools received a kit of materials containing the DVD, discussion guide, screening forms, and other educational and promotional items. The goals of the program were to increase an understanding of depression and suicide, improve attitudes towards intervening with peers, and encourage youth who are contemplating suicide to seek help.; Comparator: Schools assigned to wait-list control; Study period: 2007-2008 and 2008-2009 school years; Length of follow-up: 3 months | N=1,302; Age (years, mean): in 9^th^ grade; Gender (% male): 58; Race (%): White 60%, Hispanic 23%, Black 6%; Military status: NR; Housing status: NR; Socioeconomic status: almost 1/3 qualified for free/reduced lunches; Mental health diagnoses: NR; Prior suicide behavior: 8% treated for depression/suicidal ideation, 8% ideation in past 3 months, 7% suicide plan in past 3 months, 2% attempt in past 3 months, 8% lifetime attempt
Wasserman 2015^32^ (SEYLE trial); Country: Austria, Estonia, France, Germany, Hungary, Ireland, Italy, Romania, Slovenia, Spain; Study Design: Cluster RCT; Intervention Type: Social-Emotional Learning Program; Setting: High School; Funding: Government; Risk of Bias: Low | Inclusion: Public schools containing at least 40 pupils aged 15 years, had more than 2 teachers for pupils aged 15 years, and had no more than 60% of pupils of the same sex. Within the schools, all classes with pupils aged mainly 15 years were approached for participant recruitment. To avoid discrimination, all pupils in the participating classrooms, including those aged 14 to 16 years, were also approached for recruitment.; Exclusion: All pupils who reported suicide attempts ever, or severe ideation in the past 2 weeks before the baseline assessment, and those with missing data regarding these 2 variables were not included in the final analysis. | Intervention: Schools were assigned to 1 of 3 interventions.; Questions, Persuade, and Refer was a gatekeeper training module targeting teachers and other school personnel to recognize the risk of suicidal behavior and motivate and help pupils seek help; The Youth Aware of Mental Health Program targeted pupils and including interactive workshops, educational posters, and lectures about mental health; At-risk pupils were referred for professional screening based on responses to the baseline questionnaire; Comparator: Control group was exposed to educational posters displayed in their classrooms; Study period: November 1, 2009-December 14, 2010; Length of follow-up: 12 months | N=5,654 adolescents (85 schools) randomized to Youth Aware of Mental Health or control group; Age (years, mean): 15; Gender (% male): 42; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: 10% pupils’ parents lost employment in prior year; Mental health diagnoses: NR; Prior suicide behavior: Pupils with prior suicide attempt or severe suicide ideation were excluded from analysis
Milner 2019^33^; Country: Australia; Study Design: RCT; Intervention Type: Social-Emotional Learning Program; Setting: Workplace (construction); Funding: Foundation; Risk of Bias: Medium | Inclusion: Adult men workers in the construction industry consecutively accessing services from Incolink (social welfare trustee company that provides support to unemployed members of the construction industry) between 30 May 2016 and 4 April 2017 who owned a smartphone with Internet connectivity and adequate data download capacity; Exclusion: <18 years of age with inadequate English | Intervention: Contact+Connect; an electronic intervention designed to reduce stigma against mental health problems delivered to participants’ smart phones. One text message was delivered per week for 6 weeks, containing links to resources.; Comparator: Wait-list (received the intervention materials in full at the conclusion of the intervention period); Study period: NR (around 2016-2017); Length of follow-up: 6 weeks | N=682 randomized; Age (years, mean):; Aged 18-29 11%; Aged 30-39 23%; Aged 40-49 32.5%; Aged 50-59 24%; Aged 60+ 9%; Gender (% male): 100%; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: Unemployed 77%; Mental health diagnoses: NR; Prior suicide behavior: Attempted suicide 1.4%; Communicated suicide 1.7%
Rogers 2018^62^; Country: United States; Study Design: RCT; Intervention Type: Social-Emotional Learning Program; Setting: University research pools and surrounding community; Funding: Government, foundation; Risk of Bias: Medium | Inclusion: aged 18 to 69, recruited from undergraduate psychology student research pools (n= 114) and the surrounding community (n= 152).; Exclusion: NR | Intervention: Psychoeducation; Participants browsed the National Suicide Prevention Lifeline. This website provides information about suicide statistics, risk factors, and resources related to prevention.; Intervention: Interpersonal exposure; Participants browsed the Live Through This project website. This website contains photographed portraits of suicide attempters and detailed firsthand accounts, personal stories, and interviews about their lives and suicidal history.; Comparator: Participants browsed the National Diabetes Education site; Study period: NR; Length of follow-up: 1 month | N=266 randomized; Age (years, mean): 26; Gender (% male): 35; Race (%): 67% White, 20% Black, 14% Hispanic, 6% Asian, 4% Native American, 2% other; Military status: NR; Housing status: NR; Socioeconomic status: 11% income <$10,000, 18% income $10,000 to <$25,000, 15% income $25,000 to <$40,000, 17% income $40,000 to <$75,000, 15% income $75,000 to <$100,000, 12% income $100,000 to <$150,000, 11% income ≥$150,000; Mental health diagnoses: NR; Prior suicide behavior: 38% lifetime suicide ideation, 12% lifetime suicide plan, 9% lifetime suicide attempt
Taylor-Rodgers 2014^61^; Country: Australia; Study Design: RCT; Intervention Type: Social-Emotional Learning Program; Setting: Recruited on University campus and social media; Funding: Government; Risk of Bias: Medium | Inclusion: Age 18-25 years.; Exclusion: NR | Intervention: Online psychoeducation on depression, anxiety, and suicide with vignettes of young people experiencing mental health problems. Program lasted 3 weeks.; Comparator: Online attention-matched control information (emailed links to webpages on dental hygiene, common household medications and nutrition facts).; Study period: NR; Length of follow-up: 4 weeks | N=67 randomized; Age (years, mean): 22; Gender (% male): 25; Race (%): 78% White, 16% Asian, 6% other; Military status: NR; Housing status: NR; Socioeconomic status: NR; 9% no university, 82% bachelor’s degree, 9% post-graduate education; Mental health diagnoses: NR; Prior suicide behavior: NR
Voss 2013^63^; Country: United States; Study Design: Pre-post observational with no concurrent control; Intervention Type: Social-Emotional Learning Program; Setting: Intensive outpatient program for addiction treatment; Funding: Government (National Institute on Drug Abuse); Risk of Bias: Medium | Inclusion: attendance at a publicly funded addiction treatment agency in Washington State; Exclusion: 1) imminently suicidal patients or those who planned or attempted suicide within the past 3 months 2) patients with cognitive or language barriers judged severe enough to impede participation | Intervention: Preventing Addiction Related Suicide is a group-based program implemented by counselors in the intensive outpatient program for addiction treatment. The session took place over a single 2-3 hour session consisting of didactive material and discussion. The program provides participants with an overview of factors related to suicide risk and steps 1 can take to address current suicide risk in oneself or others.; Comparator: Pre-intervention; Study period: months and years of data collection were not reported; Length of follow-up: immediately after the program and 1 month later | N=78; Age (years, mean): 35; Gender (% male): 64; Race (%): Caucasian (44%), African American (26%), Asian (8%), American Indian/Alaskan Native (5%), >1 race (6%), did not report race (8%); Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: all participants were part of an addiction treatment program; Prior suicide behavior: several participants reported prior suicide attempts

NR=not reported; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe trial

Appendix Table 5-18 Social-Emotional Learning Programs: Risk of bias – Cluster RCTs

Author, Year | Sequence Generation | Allocation Concealment | Recruitment Bias | Baseline Imbalance | Blinded Outcome Assessment | Incomplete Cluster Data | Incomplete Outcome Data | Selective Outcome Reporting | Overall Risk of Bias
Schilling 2016^31^ | Unclear (NR) | Unclear (NR) | Low (students participating prior to being randomized) | High (race/ethnicity and gender) | Unclear (NR) | Low | High; (28% in the control arm and 10% in the intervention arm not available for post-test) | Low | Medium
Wasserman 2015^32^ (SEYLE) | Low (random number generator) | Unclear (NR) | Low (recruitment prior to being randomized) | Low | Unclear (NR) | Low | Moderate (19% not available at the 12-month follow-up) | Low | Medium

NR=not reported; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe trial

Appendix Table 5-19 Social-Emotional Learning Programs: Risk of Bias – RCTs

Author, Year | Random sequence generation | Allocation concealment | Blinding of participants, personnel, and outcome assessors | Incomplete outcome data | Selective outcome reporting | Other sources of bias | Overall Risk of Bias
Milner 2019^33^ | Low (Adequate) | Low | Low | Medium | Low | - | Medium
Rogers 2018^62^ | Unclear | Unclear | High | Low | Low | Low | Medium
Taylor-Rodgers 2014^61^ | Low | Unclear | Low | Medium (16% lost to follow-up. All subjects were analyzed.) | Unclear | Low | Medium
Han 2018^75^ | Low | Low | Low | High | Low | Low | High
Dueweke 2017^76^ | Low | High | Unclear | Low | Low | Low | High

RCT=randomized controlled trial

Appendix Table 5-20 Social-Emotional Learning Programs: Risk of Bias – Non-RCTs^*^

Author, Year | Did the study include all eligible participants or were the participants a representative sample from the population of interest? | Were the participants included in any comparison similar? | Were the participants included in any comparisons receiving similar treatment/ care, other than the exposure or intervention of interest? | Was the control group concurrent? | For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/exposure? | Was follow-up complete? | Was completeness of follow-up similar for study groups? | Were the outcomes of participants included in any comparisons measured in the same way? | Were suicide deaths and/or attempts measured in a reliable way? | Were other eligible outcomes measured in a reliable way? | Did the study adjust for confounding variables? | Overall Risk of Bias
Voss 2013^63^ | Yes | Yes | NA | NA | Yes | Yes | NA | Yes | NA | Yes | No | Medium
Freedenthal 2010^77^ | Yes | No | Unclear | Yes | NA | No | Yes | Yes | No | NA | No | High
Gravesteinj 2011^78^ | Yes | No | Yes | Yes | No | NA | NA | Yes | No | No | Unclear | High
Kennedy 2020^79^ | Unclear | Yes | Yes | No | No | No | NA | Yes | NA | Yes | No | High

* Modification of the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies

NA=not applicable; RCT=randomized controlled trial

Appendix Table 5-21 Social-Emotional Learning Programs: Suicide Deaths and Attempts from RCTs

Author, Year; Study; Design | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study; Design | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study; Design | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Schilling 2016^31^; Cluster RCT | NR | NR | NR | NR | NR | NR | Past 3 months:; 1.8% (13/719) | Past 3 months:; 1.7% (11/650) | Past 3 months:; 2.5% (14/553) | Past 3 months:; 5.0% (20/396) | NR | Past 3 months:; P<.05
Schilling 2016^31^; Cluster RCT | NR | NR | NR | NR | NR | NR | Lifetime:; 7.7% (56/719) | Lifetime:; 8.3% (54/650) | Lifetime:; 9.4% (52/553) | Lifetime:; 14.9% (59/396) | NR | Lifetime:; P<.05
Wasserman 2015^32^ (SEYLE); Cluster RCT | No completed suicides were reported for any study participants | | | | NR | NR | NA (only looked at incident suicide behavior) | 3 months:; 0.88% (19/2166); 12 months:; 0.70% (14/1987) | NA (only looked at incident suicide behavior) | 3 months:; 1.14% (27/2366); 12 months:; 1.51% (34/2256) | NR | 3 months:; OR=0.78 (95% CI 0.42 to 1.44); 12 months:; OR=0.45 (95% CI 0.24 to 0.85); No effect modification by sex (interaction test P=.27) and age (interaction test P=.89)
Milner 2019^33^; RCT | NR | NR | NR | NR | NR | NR | Suicide attempts was measured using a Likert-scale from strongly agree to strongly disagree to the question “Have you tried to kill yourself in the past 6 months?” (asked at baseline) and “…since joining the project?” (asked at post-intervention).; [underlined: Intervention over time]; MD from baseline unadjusted = 0.04; (95% CI −0.10 to 0.18); MD from baseline adjusted = 0.06; (95% CI −0.09 to 0.20); [underlined: Control over time]; MD from baseline unadjusted = 0.03; (95% CI −0.08 to 0.14); MD from baseline adjusted = 0.02; (95% CI −0.10 to 0.14); [underlined: Intervention vs control]; MD intervention vs control unadjusted = 0.01; (95% CI −0.16 to 0.19); MD intervention vs control adjusted = 0.04; (95% CI −0.15 to 0.22)
Rogers 2018^62^; RCT | NR | NR | NR | NR | NR | NR | NR | NR | NR | NR | NR | NR
Taylor-Rodgers 2014^61^; RCT | NR | NR | NR | NR | NR | NR | NR | NR | NR | NR | NR | NR

CI=confidence interval; MD=mean difference; NA=not applicable; NR=not reported; OR=odds ratio; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe trial

Appendix Table 5-22 Social-Emotional Learning Programs: Suicides Deaths and Attempts from Non-RCTs with No Concurrent Control

Author, Year; Study Design | Suicide Deaths | | | Suicide Attempts
Author, Year; Study Design | Pre-Intervention | Post-Intervention | Pre vs Post Comparison | Pre-Intervention | Post-Intervention | Pre vs Post Comparison
Voss 2013^63^; Pre-post observational with no concurrent control | NR | NR | NR | NR | NR | NR

NR=not reported; RCT=randomized controlled trial

Appendix Table 5-23 Social-Emotional Learning Programs: Secondary Outcomes

Author, Year; Study Design; Intervention Type | Stigma Towards Suicide | Caregiver Burden | Cost | Substitution (Alternative Method)
Schilling 2016^31^; Cluster RCT | NR | NR | NR | NR
Wasserman 2015^32^ (SEYLE); Cluster RCT | NR | NR | NR | NR
Milner 2019^33^; RCT | NR | NR | NR | NR
Rogers 2018^62^; RCT | Stigma of Suicide Scale; Score (SD), n; Psychoeducation arm; Pre: 62.0 (22.0), n=90; Post: 57.5 (22.8), n=90; 1 month: 60.3 (22.6), n=80; Exposure arm; Pre: 65.6 (23.7), n=86; Post: 60.6 (23.5), n=86; 1 month: 63.3 (22.9), n=76; Control arm; Pre: 61.5 (23.0), n=90; Post: 60.2 (25.1), n=90; 1 month: 67.7 (25.6), n=82; The 2 interventions resulted in a significantly greater decrease in stigma of suicide compared with the control at all timepoints (T1-T3 P<.001) | NR | NR | NR
Taylor-Rodgers 2014^61^; RCT | Stigma of Suicide Scale; Score (SD), n; Psychoeducation; Pre: 2.8 (0.4), n=34; Control; Pre: 2.8 (0.3), n=33; Difference between psycho-intervention and control at post-test was non-statistically significant (P=.619). N= 56 participants with post-test survey data | NR | NR | NR
Voss 2013^63^; Pre-post observational with no concurrent control | Stigma and Bias Towards Suicides Acts or Persons; Score (SE); Pre: 19.29 (0.44); Post: 15.57 (0.57); 1-month: 17.26 (0.60); N=64 participants with follow-up; Better attitudes towards suicidal acts or persons immediately following the session (P=.000) and 1-month post (P=.0001) compared to prior to the session | NR | NR | NR

NR=not reported; RCT=randomized controlled trial; SD=standard deviation; SE=standard error; SEYLE=Saving and Empowering Young Lives in Europe trial

Appendix Table 5-24 Social-Emotional Learning Programs: Strategies to Deliver, Sustain, and Improve the Quality of Intervention^*^

Author, Year; Study Design | Strategies to Deliver the Intervention | Strategies to Sustain the Intervention | Strategies to Improve the Quality of the Intervention
Schilling 2016^31^; Cluster RCT | School counselors and social work staff completed a 1-day training prior to administering the program.; Schools received a kit of materials containing the DVD (dramatizations of reactions to a young person who is depressed and suicidal, along with real world interviews and experiences), discussion guide, screening forms and other educational/promotional items. They also received a procedure manual for program implementation and potential solutions to anticipated barriers. | Program was implemented as part of routine health class curriculum received by all students. | Recommended “booster” programs for longer-term follow-up.; Recommended integrating adjunct elements into the program that address risk factors such as alcohol abuse, anger recognition & management, and violence reduction.
Wasserman 2015^32^ (SEYLE); Cluster RCT | Local teams were trained in the study methods and a steering group monitored adherence (process assessments and quality control—though limited detail given). The program required students to be active participants (role play).; Procedure manual was provided to all sites. | Embedded into classroom-based curriculum (5 hours in 4 weeks). | Recommended evaluation of booster activities and combination of different interventions.

RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe trial

* We abstracted this information from studies that found an intervention to be effective (defined as yielding at least low certainty evidence on reducing suicide deaths or attempts).

Appendix Table 5-25 Gatekeeper Training: Study Characteristics

Author, Year; Country; Study Design; Intervention Type; Setting; Funding; Risk of Bias | Inclusion/Exclusion Criteria | Intervention; Comparator; Study Period; Length of Follow-up | Demographics
Wasserman 2015^32^ (SEYLE trial); Country: Austria, Estonia, France, Germany, Hungary, Ireland, Italy, Romania, Slovenia, Spain; Study Design: Cluster RCT; Intervention Type: Gatekeeper training; Setting: School; Funding: Government; Risk of Bias: Low | Inclusion: Public schools containing at least 40 pupils aged 15 years, had more than 2 teachers for pupils aged 15 years, and had no more than 60% of pupils of the same sex. Within the schools, all classes with pupils aged mainly 15 years were approached for participant recruitment. To avoid discrimination, all pupils in the participating classrooms, including those aged 14 to 16 years, were also approached for recruitment.; Exclusion: All pupils who reported suicide attempts ever, or severe ideation in the past 2 weeks before the baseline assessment, and those with missing data regarding these 2 variables were not included in the final analysis. | Intervention: Schools were assigned to 1 of 3 interventions. Questions, Persuade, and Refer was a gatekeeper training module targeting teachers and other school personnel to recognize the risk of suicidal behavior and motivate and help pupils seek help; The Youth Aware of Mental Health Program targeted pupils and including interactive workshops, educational posters, and lectures about mental health At-risk pupils were referred for professional screening based on responses to the baseline questionnaire; Comparator: Control group was exposed to educational posters displayed in their classrooms; Study period: November 1, 2009-December 14, 2010; Length of follow-up: 12 months | N=5,625 adolescents (80 schools) randomized to gatekeeper or control; Age (years, median): 15; Gender (% male):41; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: 10% pupils had parents that lost employment in previous year; Mental health diagnoses: NR; Prior suicide behavior: Pupils with prior suicide attempt or severe suicide ideation were excluded
Sareen 2013^34^; Country: Canada; Study Design: RCT; Intervention Type: Gatekeeper training; Setting: Community (First nations); Funding: Government; Risk of Bias: Medium | Inclusion: Members of the Swampy Cree tribal communities who were currently residing on the reserves; Exclusion: <16 years of age, prior training in SafeTALK (a briefer version of suicide awareness training) or Applied Suicide Intervention Skills Training, being an elected official in a First Nations community, living off reserve, and an inability to read or write English. | Intervention: Applied Suicide Intervention Skills Training, A 2-day intensive, interactive and practice-dominated workshop aimed at enabling people to recognize risk and learn how to intervene immediately to prevent suicide.; Comparator: Resilience Retreat, a 2-day retreat that was divided into cultural teachings and activities, sharing circles, small group discussions, and storytelling.; Study period: years NR (sample recruited from 2010-2011); Length of follow-up: 6 months | N=55; Age (years, mean): NR; Aged 16-21 44%; Aged 22-44 33%; Aged 45+ 22%; Gender (% male): 40%; Race (%): First nations (Cree) 100%; Military status: NR; Housing status: NR; Socioeconomic status: Working full or part time 25%; Unemployed/social assistance 45%; Educational attainment grade 9 or lower: 40%; Mental health diagnoses: NR; Prior suicide behavior: NR
Garraza 2019^37^ (long-term suicides); Walrath 2015^35^ (short-term suicides); Garraza 2015^36^ (suicide attempts); Garraza 2018^72^ (cost-benefit); Country: United States; Study Design: Observational with concurrent control; Intervention Type: Gatekeeper training; Setting: General community (activities took place in multiple settings); Funding: Government; Risk of Bias: Low; Note: All 4 articles evaluated the Garrett Lee Smith program. They used overlapping datasets and time periods. We considered them to be the same single study to avoid double-counting data. We used Garraza 2019 to extract long-term suicide deaths, Garraza 2015 for suicide attempts, and Garraza 2018 for cost-benefit analysis. | Inclusion: Counties exposed to the suicide prevention efforts of the Garrett Lee Smith program at some point between 2006 and 2009 (intervention counties) and counties that shared key characteristics but were not exposed to these suicide prevention efforts (control counties).; For suicide mortality, the authors explicitly stated that counties had to have more than 3,000 youths (aged 10-24) to be included as smaller counties had large variability of youth suicide mortality rates.; Exclusion: Nothing additional | Intervention: Garrett Lee Smith Suicide Prevention Program-gatekeeper training is a core part of the program. Intervention group was defined as a county conducting a Garrett Lee Smith-funded gatekeeper training event targeting youths/young adults. Though, the program is usually implemented in concert with other prevention strategies.; Comparator:; 1) Counties that did not implement the Garrett Lee Smith Program; 2) Adult populations who were not the target of the program; Study period: Initially exposed to the program between 2006 and 2009; Length of follow-up: 4 years for suicide deaths outcome; ≥2 years for attempts | [underlined: Baseline Characteristics After Matching as Reported in Garraza 2019]; N=80,300 youths; 231,200 adults; N=481 exposed countries; 851 unexposed counties; Age (years, mean): NR; Gender (% male): only reported in the initial analysis in Walrath 2015, 49% male; Race (%): 85% White; 10% Black/African American; 6% Hispanic; 2% American Indian/Alaskan Native; Military status: NR; Housing status: NR; Socioeconomic status: 5% unemployment rate; 14% poverty rate; ~$39,000 median household income; 17% uninsured rate; Mental health diagnoses: NR; Prior suicide behavior: youth suicide rate 8.5 per 100,000; adult rate 17.6/100,00; [underlined: Baseline Characteristics After Matching as Reported in Garraza 2015]; N=141,000 persons; N=466 intervention counties; 1161 control; Age (years, mean): 12% 12-17 years; 15% 18-25 years; 73% ≥26 years; Gender (% male): 48%; Race (%): 81% Non-Hispanic White; 9% Non-Hispanic African American; 2% Non-Hispanic American Indian or Alaskan Native; <1% Non-Hispanic Native Hawaiian and other Pacific Islander; 1% Non-Hispanic Asian; 1% Non-Hispanic multiracial/multiethnic; 5% Hispanic; Military status: NR; Housing status: NR; Socioeconomic status:; 23% family income <20000; 38% between 20,000 and 49,999; 18% between 50,000 and 74,999; 21% 75,000 or more; 50% employed full-time; 14% employed part-time; 4% unemployed; 32% other (eg, not in labor force); 85% have health insurance; Mental health diagnoses: 15% lifetime major depressive episode; 8% past year major depressive episode; Prior suicide behavior: ~10 attempts per 1000 youths aged 16-23 years; ~6 attempts per 1000 adults aged ≥24 years

NR=not reported; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

Appendix Table 5-26 Gatekeeper Training: Risk of bias – Cluster RCTs

Author, Year | Sequence Generation | Allocation Concealment | Recruitment Bias | Baseline Imbalance | Blinded Outcome Assessment | Incomplete Cluster Data | Incomplete Outcome Data | Selective Outcome Reporting | Overall Risk of Bias
Wasserman 2015^32^ (SEYLE) | Low (random number generator) | Unclear (NR) | Low (recruitment prior to randomization | Low | Unclear (NR) | Low | Moderate (19% not available at the 12-month follow-up period) | Low | Medium

NR=not reported; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

Appendix Table 5-27 Gatekeeper Training: Risk of Bias – RCTs

Author, Year | Random sequence generation | Allocation concealment | Blinding of participants, personnel, and outcome assessors | Incomplete outcome data | Selective outcome reporting | Other sources of bias | Overall Risk of Bias
Sareen 2013^34^ | Low (Adequate) | Unclear | Unclear | Low | Low | - | Medium

RCT=randomized controlled trial

Appendix Table 5-28 Gatekeeper Training: Risk of Bias – Non-RCTs^*^

Author, Year | Did the study include all eligible participants or were the participants a representative sample from the population of interest? | Were the participants included in any comparison similar? | Were the participants included in any comparisons receiving similar treatment/ care, other than the exposure or intervention of interest? | Was the control group concurrent? | For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/exposure? | Was follow-up complete? | Was completeness of follow-up similar for study groups? | Were the outcomes of participants included in any comparisons measured in the same way? | Were suicide deaths and/or attempts measured in a reliable way? | Were other eligible outcomes measured in a reliable way? | Did the study adjust for confounding variables? | Overall Risk of Bias
Garraza 2019^37^; Walrath 2015^35^; Garraza 2015^36^; Garraza 2018^72^ | Yes | Yes | Unclear | Yes | NA | NA | NA | Yes | Yes (deaths) Unclear (attempts) | Yes (cost) | Yes | Low
Smith Osborne 2017^80^ | Unclear | No | No | NA | No | NA | NA | Unclear | Unclear | Yes | Yes | High

* Modification of the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies

NA=Not applicable; RCT=randomized controlled trial

Appendix Table 5-29 Gatekeeper Training: Suicide Deaths and Suicide Attempts Outcomes from RCTs

Author, Year; Study; Design | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study; Design | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study; Design | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Wasserman 2015^32^ (SEYLE); Cluster RCT | No completed suicides were reported for any study participants | | | | NR | NR | NA; only looked at incident suicide attempt | 3 months:; 0.68% (15/ 2209); 12 months:; 1.11% (22/ 1978) | NA; only looked at incident suicide attempt | 3 months:; 1.14% (27/ 2366); 12 months:; 1.51% (34/ 2256) | NR | 3 months:; OR=0.62 (95% CI 0.32 to 1.18); 12 months:; OR=0.70 (95% CI 0.39 to 1.25); No effect modification by sex (interaction test P=.27) and age (interaction test P=.89)
Sareen 2013^34^; RCT | NR | 6 months:; 0% (0/31) | NR | 6 months:; 0% (0/24) | NR | P=1.0 | lifetime attempt:; 19% (6/31) | 6 months:; 0% (0/28) | lifetime attempt:; 25% (6/24) | 6 months:; 0% (0/22) | NR | P=1.0

CI=confidence interval; NA=not applicable; NR=not reported; OR=odds ratio; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

Appendix Table 5-30 Gatekeeper Training: Suicide Deaths and Suicide Attempts from Non-RCTs with Concurrent Control

Author, Year; Study Design | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study Design | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study Design | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Garraza 2019^37^; Walrath 2015^35^; Garraza 2015^36^; Garraza 2018^72^; Observational with concurrent control | Suicides among youths 10-24 years old as reported in Garraza 2019; Reported as difference per 100,000 between intervention and control; At 1 year: −0.893 (SE=0.408; P=.029); At 2 years: −1.095 (SE=0.422; P=.010); At 3 years: −0.431 (SE=0.481; P=.370); At 4 years: −0.324 (SE=0.477; P=.498); Suicides among youths in rural counties as reported in Garraza 2019; Reported as difference per 100,000 between intervention and control; At 1 year: −0.803 (SE=0.768; P=.296); At 2 years: −2.936 (SE=0.807; P<.001); At 3 years: −0.671 (SE=0.836; P=0.422); At 4 years: −1.016 (SE=0.791; P=.199) | | | | | | Attempts among youths 16-23 years old as reported in Garraza 2015; Reported as difference per 1,000 between intervention and control; At 1 year: −4.91 (SE=1.57; P=.003); At ≥2 years: −1.19 (SE=1.87; P=.53); Attempts among youths 16-19 years old as reported in Garraza 2015; Reported as difference per 1,000 between intervention and control; At 1 year: −4.46 (SE=2.14; P=.042); At ≥2 years: −2.70 (SE=2.98; P=.369); Attempts among youths 20-23 years old as reported in Garraza 2015; Reported as difference per 1,000 between intervention and control; At 1 year: −5.68 (SE=2.46; P=.025); At ≥2 years: 3.09 (SE=3.63; P=.399)

SE=standard error; RCT=randomized controlled trial

Appendix Table 5-31 Gatekeeper Training: Secondary Outcomes

Author, Year; Study Design | Stigma Towards Suicide | Caregiver Burden | Cost | Substitution; (Alternative Method)
Wasserman 2015^32^ (SEYLE); Cluster RCT | NR | NR | NR | NR
Sareen 2013^34^; RCT | NR | NR | NR | NR
Garraza 2019^37^; Walrath 2015^35^; Garraza 2015^36^; Garraza 2018^72^; Observational with concurrent control | NR | NR | As reported in Garraza 2018; Cost savings from averted hospitalizations; $187.8 million (95% CI, 67.1 to 308.5); Cost savings from averted emergency department visits; $34.1 million (95% CI, 8.7 to 59.9); Total medical cost savings; $222.1 million (95% CI, 78.7 to 365.4); Total Garrett Lee Smith program costs; $49.4 million; Benefit-cost ratio; $4.5 (95% CI, 1.6 to 7.4) | NR

CI=confidence interval; NR=not reported; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

Appendix Table 5-32 Gatekeeper Training: Strategies to Deliver, Sustain, and Improve the Quality of Intervention^*^

Author, Year; Study Design | Strategies to Deliver the Intervention | Strategies to Sustain the Intervention | Strategies to Improve the Quality of the Intervention
Wasserman 2015^32^ (SEYLE); Cluster RCT | Local teams were trained in the study methods and a steering group monitored adherence (process assessments and quality control—though limited detail given).; Power point presentations and booklet were distributed to all trainees. | Embedded into school setting. | Recommended evaluation of booster activities and combination of different interventions.

RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

* We abstracted this information from studies that found an intervention to be effective (defined as yielding at least low certainty evidence on reducing suicide deaths or attempts).

Appendix Table 5-33 Crisis Intervention: Study Characteristics

Author, Year; Country; Study Design; Intervention Type; Setting; Funding; Risk of Bias | Inclusion/Exclusion Criteria | Intervention; Comparator; Study Period; Length of Follow-up | Demographics
Stacks 2015^38^; Country: United States; Study Design: Pre-post observational with no concurrent control; Intervention Type: Crisis intervention; Setting: Suicide hotspot; Funding: NR; Risk of Bias: Medium | Inclusion: Yearly suicide counts at Skyway Bridge from the period 1954 (the year the bridge opened) through 2012.; Exclusion: Year 1999 was omitted from the analysis because the phones were installed in 1999. | Intervention: Phones were installed on the Skyway Bridge in St. Petersburg, Florida – with direct links to a crisis center counselor; Comparator: Pre-intervention; Study period: 1954-2013; Length of follow-up: ~13 years. Crisis phones were installed in July, 1999 | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR

NR=not reported

Appendix Table 5-34 Crisis Intervention: Risk of Bias – Non-RCTs^*^

Author, Year | Did the study include all eligible participants or were the participants a representative sample from the population of interest? | Were the participants included in any comparison similar? | Were the participants included in any comparisons receiving similar treatment/ care, other than the exposure or intervention of interest? | Was the control group concurrent? | For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/exposure? | Was follow-up complete? | Was completeness of follow-up similar for study groups? | Were the outcomes of participants included in any comparisons measured in the same way? | Were suicide deaths and/or attempts measured in a reliable way? | Were other eligible outcomes measured in a reliable way? | Did the study adjust for confounding variables? | Overall Risk of Bias
Stacks 2015^38^ | Yes | Unclear | Unclear | No | Yes | NA | NA | Unclear | Yes | NA | Unclear | Medium

* Modification of the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies

NA=not applicable; RCT=randomized controlled trial

Appendix Table 5-35 Crisis Intervention: Suicide Deaths and Attempts from Non-RCTs with No Concurrent Control

Author, Year; Study Design | Suicide Deaths | | | Suicide Attempts
Author, Year; Study Design | Pre-Intervention | Post-Intervention | Pre vs Post Comparison | Pre-Intervention | Post-Intervention | Pre vs Post Comparison
Stacks 2015^38^; Pre-post observational with no concurrent control | 1986-1998:; 48 suicides | 2000-2012:; 106 suicides | 2000-2012:; +4.46 suicides/year vs 1986-1998; P<.001; +2.73 suicides/year vs 1986-1998 when adjusting for Florida suicide rate; P<.05; 2000-2001:; −5.0 suicides/year vs 1997-1998; not statistically significant | NR | NR | NR

NR=not reported; RCT=randomized controlled trial

Appendix Table 5-36 Crisis Intervention: Secondary Outcomes

Author, Year; Study Design | Stigma Towards Suicide | Caregiver Burden | Cost | Substitution (Alternative Method)
Stacks 2015^38^; Pre-post observational with no concurrent control | NR | NR | NR | NR

NR=not reported

Appendix Table 5-37 Public Awareness and Education Campaigns: Study Characteristics

Author, Year; Country; Study Design; Intervention Type; Setting; Funding; Risk of Bias | Inclusion/Exclusion Criteria | Intervention; Comparator; Study Period; Length of Follow-up | Demographics
Matsubayashi 2014^40^; Country: Japan; Study Design: Pre-post observational with no concurrent control; Intervention Type: Public awareness and education campaign; Setting: Community; Funding: Foundation; Risk of Bias: Low | Inclusion: Resident of Nagoya Japan.; Exclusion: NR | Intervention: Public awareness campaign as part of a city-wide suicide prevention program in the city of Nagoya Japan. Promotional materials that were aimed to stimulate public awareness of depression and promote care- seeking behavior were distributed to residents during 2010-2012. Materials were handed out to pedestrians on city streets and commuters in train stations.; Comparator: None; Study period: 2010-2012; intervention effects measured at 5 months | N=2.3 million (population of Nagoya); Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: 448 people died by suicide in 2010, rate of 20.3. per 100,000
Till 2013^39^; Country: Austria; Study Design: Observational with concurrent control; Intervention Type: Public awareness and education campaign; Setting: Community; Funding: NR; Risk of Bias: Medium | Inclusion: Resident of the Styria region of Austria; Exclusion: NR | Intervention: Suicide awareness campaign in the Austrian federal state of Styria to increase help-seeking behavior in the population via a telephone counseling service providing support 24/7 for all people in all kinds of crises, including individuals at risk for suicide.; Comparator: Federal state of Upper Austria with its own telephone crisis service was used as the control region; Study period: January to June 2011; Length of follow-up: 3 months pre-intervention and 3 months post | N=2.6 million in both study and control areas in 2011; Age (years, mean): 20% age 0-18, 58% age 19-60, 22% age 61+; Gender (% male): 49%; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: Unemployment rates 4-6.3%; Mental health diagnoses: NR; Prior suicide behavior: 17.5 suicides per 100,000 in study area; 15.1 suicides per 100,000 in control area

NR=not reported

Appendix Table 5-38 Public Awareness and Education Campaigns: Risk of Bias – Non-RCTs^*^

Author, Year | Did the study include all eligible participants or were the participants a representative sample from the population of interest? | Were the participants included in any comparison similar? | Were the participants included in any comparisons receiving similar treatment/ care, other than the exposure or intervention of interest? | Was the control group concurrent? | For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/ exposure? | Was follow-up complete? | Was completeness of follow-up similar for study groups? | Were the outcomes of participants included in any comparisons measured in the same way? | Were suicide deaths and/or attempts measured in a reliable way? | Were other eligible outcomes measured in a reliable way? | Did the study adjust for confounding variables? | Overall Risk of Bias
Till 2013^39^ | Yes | Yes | Unclear | Yes | NA | Yes | Yes | NA | Unclear | NA | No | Medium
Matsubayashi 2014^40^ | Yes | Yes | Yes | NA | Yes | NA | NA | Yes | Yes | NA | Unclear | Low

* Modification of the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies

NA=Not applicable; RCT=randomized controlled trial

Appendix Table 5-39 Public Awareness and Education Campaigns: Suicide Deaths and Attempts from Non-RCTs with Concurrent Control

Author, Year; Study Design | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study Design | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study Design | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Till 2013^39^; Observational with concurrent control | 3 months before campaign: 52 | 3 months after campaign: 69 | 3 months before campaign: 67 | 3 months after campaign: 68 | [underlined: Intervention]; +32.6%; [underlined: Control]; +1.4% | P=.28 | NR | NR | NR | NR | NR | NR

NR=not reported; RCT=randomized controlled trial

Appendix Table 5-40 Public Awareness and Education Campaigns: Suicide Deaths and Attempts from Non-RCTs with No Concurrent Control

Author, Year; Study Design; Intervention Type | Suicide Deaths | | | Suicide Attempts
Author, Year; Study Design; Intervention Type | Pre-Intervention | Post-Intervention | Pre vs Post Comparison | Pre-Intervention | Post-Intervention | Pre vs Post Comparison
Matsubayashi 2014^40^; Pre-post observational with no concurrent control | Reference = months with no campaign activity | Notes:; Men: The effect of the campaign lasts for 4 months, but not more than 5 months; Women: The only statistically significant reduction in the number of suicides was observed in the second month during the post-distribution period. | Ward with a campaign 0 months earlier 0 month: IRR= ~1.005 (95% CI 0.99 to 1.02); Estimated from figure; Ward with a campaign 2 months earlier:; IRR = 0.971 (95% CI 0.957 to 0.985); Ward with a campaign; 5 months earlier: IRR = ~0.995 (95% CI 0.97 to 1.02); Estimated from figure | NR | NR | NR

CI=confidence interval; IRR=incident rate ratio; NR=not reported; RCT=randomized controlled trial

Appendix Table 5-41 Public Awareness and Education Campaigns: Secondary Outcomes

Author, Year; Study Design | Stigma Towards Suicide | Caregiver Burden | Cost | Substitution (Alternative Method)
Till 2013^39^; Observational with concurrent control | NR | NR | NR | NR
Matsubayashi 2014^40^; Pre-post observational with no concurrent control | NR | NR | NR | NR

NR=not reported

Appendix Table 5-42 Screening for At-Risk: Study Characteristics

Author, Year; Country; Study Design; Intervention Type; Setting; Funding; Risk of Bias | Inclusion/Exclusion Criteria | Intervention; Comparator; Study Period; Length of Follow-up | Demographics
Wasserman 2015^32^ (SEYLE trial); Country: Austria, Estonia, France, Germany, Hungary, Ireland, Italy, Romania, Slovenia, Spain; Study Design: Cluster RCT; Intervention Type: screening for at-risk (not in clinic setting); Setting: School; Funding: Government; Risk of Bias: Low | Inclusion: Public schools containing at least 40 pupils aged 15 years, had more than 2 teachers for pupils aged 15 years, and had no more than 60% of pupils of the same sex. Within the schools, all classes with pupils aged mainly 15 years were approached for participant recruitment. To avoid discrimination, all pupils in the participating classrooms, including those aged 14 to 16 years, were also approached for recruitment.; Exclusion: All pupils who reported suicide attempts ever, or severe ideation in the past 2 weeks before the baseline assessment, and those with missing data regarding these 2 variables were not included in the final analysis. | Intervention: Schools were assigned to 1 of 3 interventions. Questions, Persuade, and Refer was a gatekeeper training module targeting teachers and other school personnel to recognize the risk of suicidal behavior and motivate and help pupils seek help. The Youth Aware of Mental Health Program targeted pupils and including interactive workshops, educational posters, and lectures about mental health. At-risk pupils were referred for professional screening based on responses to the baseline questionnaire; Comparator: Control group was exposed to educational posters displayed in their classrooms; Study period: November 1, 2009- December 14, 2010; Length of follow-up: 12 months | N=5,697 adolescents (83 schools) randomized to screening or control group; Age (years, median): 15; Gender (% male): 43; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: 10% pupils had parents that lost employment in previous year; Mental health diagnoses: NR; Prior suicide behavior: Pupils with prior suicide attempt or severe suicide ideation were excluded
Dezso 2018^43^; Country: Europe; Study Design: Observational with concurrent control; Intervention Type: Screening for at-risk (not in clinic setting); Setting: Prison/detention facility; Funding: NR; Risk of Bias: Medium | Inclusion: All arrivals to Berlin remand prison between March and May 2016; Exclusion: transport prisoners, detainees admitted prior to the study period but who were temporarily transferred to the prison hospital for health reasons. | Intervention: Suicide screening instrument administered to arriving prisoners.; Comparator: Prisoners arriving pre-screening instrument; Study period: Participants in the intervention group entered the detention facility from March-May 2016.; Participants in the control group entered the facility December-February 2016.; Length of follow-up: 6 months; Note: the control group consisted of prisons who entered the detention facility in the 3 months prior to the screening intervention. We considered the study to have a “concurrent control” because the follow-up period overlapped between intervention and control. | N=1,510; Age (years, mean): 35; Gender (% male): 100; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Oyama 2017^42^; Country: Japan; Study Design: Observational with concurrent control; Intervention Type: Screening for at-risk (not in clinic setting); Setting: General community (rural areas/older adults); Funding: Government; Risk of Bias: Medium | Inclusion: Residents of the Aomori Prefecture in northern Japan aged 40-64 years; Exclusion: recently received a depression intervention | Intervention: Standardized work plan autonomously conducted by municipalities. Municipalities distributed public information leaflets and newsletters designed to publicize information about depression as a risk factor for suicide, explain about depression screening and treatment options, and reduce the stigma of mental illness. Depression screener mailed to all residents aged 36–64 years in districts with a history of high suicide rates. Anyone with a Self-Rating Depression Scale score of ≥48 was contacted in the second screening stage consisting of a telephone interview based on the major depressive episodes module. Interviewers summarized the results, and the psychiatrist treating the 5 municipalities rated these results for severity of depressive episode. Written feedback was mailed to all respondents, and those diagnosed with any depressive episode were contacted by health professionals and provided with a referral to a psychiatrist and support to help them continue treatment, including information about the importance of doing so.; Comparator: Municipalities without intervention; Study period: 2009-2012; Length of follow-up: 8 years | N=12,682 participants who were first stage screened in the intervention area; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Oyama 2016^41^; Country: Japan; Study Design: Observational with concurrent control; Intervention Type: Screening for at-risk (not in clinic setting); Setting: General community (rural areas/older adults); Funding: Government, foundation, university; Risk of Bias: Medium | Inclusion: Japanese adult residents of the Aomori Prefecture in northern Japan, age ≥65 years and were exposed to potential long-term effects of the initial 4-year intervention, ending in 2010.; Exclusion: NR | Intervention: Self-administered screening questionnaire administered to municipalities with high prevalence of depressive symptoms. Identified participants followed-up via telephone interview and referred for treatment. Educational component provided information on depression symptoms treatment through workshops and newsletters at community centers.; Comparator: Municipalities without intervention, usual care consisted of health check-ups; Study period: 1999-2010 (intervention period 2005-2006); Length of follow-up: 4 years | N=24,312; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR

NR=not reported; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

Appendix Table 5-43 Screening for At-Risk: Risk of bias – Cluster RCTs

Author, Year | Sequence Generation | Allocation Concealment | Recruitment Bias | Baseline Imbalance | Blinded Outcome Assessment | Incomplete Cluster Data | Incomplete Outcome Data | Selective Outcome Reporting | Overall Risk of Bias
Wasserman 2015^32^ (SEYLE) | Low (random number generator) | Unclear (NR) | Low (recruitment prior to randomization | Low | Unclear (NR) | Low | Moderate (19% not available at the follow-up period) | Low | Medium

NR=not reported; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

Appendix Table 5-44 Screening for At-Risk: Risk of Bias – Non-RCTs^*^

Author, Year | Did the study include all eligible participants or were the participants a representative sample from the population of interest? | Were the participants included in any comparison similar? | Were the participants included in any comparisons receiving similar treatment/ care, other than the exposure or intervention of interest? | Was the control group concurrent? | For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/ exposure? | Was follow-up complete? | Was completeness of follow-up similar for study groups? | Were the outcomes of participants included in any comparisons measured in the same way? | Were suicide deaths and/or attempts measured in a reliable way? | Were other eligible outcomes measured in a reliable way? | Did the study adjust for confounding variables? | Overall Risk of Bias
Dezso 2018^43^ | Yes | Yes | Yes | No | NA | Yes | Yes | Yes | NA | Yes | No | Medium
Oyama 2017^42^ | Yes | Unclear | Yes | Yes | No | Yes | Yes | Yes | Yes | NA | Yes | Medium
Oyama 2016^41^ | Yes | Yes | Yes | No | NA | Yes | Yes | Yes | Yes | NA | Yes | Medium

* Modification of the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies

NA=not applicable; RCT=randomized controlled trial

Appendix Table 5-45 Screening for At-Risk: Suicide Deaths and Attempts from RCTs

Author, Year; Study Design | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study Design | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study Design | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Wasserman 2015^32^ (SEYLE); Cluster RCT | No completed suicides were reported for any study participants | | | | NR | NR | NA (only looked at incident suicide behavior) | 3 months:; 1.23% (27/ 2203); 12 months:; 1.02% (20/ 1961) | NA (only looked at incident suicide behavior) | 3 months:; 1.14% (27/ 2366); 12 months:; 1.51% (34/ 2256) | NR | 3 months:; OR=1.10 (95% CI 0.61 to 1.97); 12 months:; OR=0.65 (95% CI 0.36 to 1.18); No effect modification by sex (interaction test P=.27) and age (interaction test P=.89)

CI=confidence interval; NA=not applicable; NR=not reported; OR=odds ratio; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

Appendix Table 5-46 Screening for At-Risk: Suicide Deaths and Attempts from Non-RCTs with Concurrent Control

Author, Year; Study Design | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study Design | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study Design | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Dezso 2018^43^; Observational with concurrent control | No suicides were reported during the 6-month study period in either the intervention or control groups.; Note: the control group consisted of prisons who entered the detention facility in the 3 months prior to the screening intervention. We considered the study to have a “concurrent control” because the follow-up period overlapped between intervention and control. | | | | | | NR | NR | NR | NR | NR | NR
Oyama 2017^42^; Observational with concurrent control | 2005-2008:; rate 64.9 per 100,000; 105 suicides | 2009-2012:; Rate 37.0 per 100,000; 59 suicides | Control areas; 2005-2008:; rate 57.9 per 100,000; 114 suicides | Control areas; 2009-2012:; rate 53.8 per 100,000; 103 suicides | [underlined: Intervention]; IRR adj = 0.57 (95% CI 0.41 to 0.78); [underlined: Control]; IRR adj = 0.93 (95% CI 0.70 to 1.23); [underlined: Country]; IRR adj = 0.93 (95% CI 0.82 to 1.06) | Ratio of IRR adj = 1.63; (95% CI 1.06 to 2.48) in control with intervention as reference | NR | NR | NR | NR | NR | NR
Oyama 2017^42^; Observational with concurrent control | | | Country; 2005-2008:; rate 33.4 per 100,000; 56,943 suicides | Country; 2009-2012:; rate 30.2 per 100,000; 51,759 suicides | [underlined: Intervention]; IRR adj = 0.57 (95% CI 0.41 to 0.78); [underlined: Control]; IRR adj = 0.93 (95% CI 0.70 to 1.23); [underlined: Country]; IRR adj = 0.93 (95% CI 0.82 to 1.06) | Ratio of IRR adj = 1.63; (95% CI 1.06 to 2.48) in control with intervention as reference | NR | NR | NR | NR | NR | NR
Oyama 2016^41^; Observational with concurrent control | 1999-2004:; range of rates 42.8 to 49.2 per 100,000 per year | 2005-2010:; range of rates 23.1 to 28.8 per 100,000 per year | 1999-2004:; range of rates: 39.9 to 41.9 per 100,000 per year | 2005-2010:; range of rates: 35.4 to 47.6 per 100,000 per year; 65 suicides | [underlined: Intervention]; IRR adj = 0.52 (95% CI 0.33 to 0.83); [underlined: Control]; IRR adj = 0.93 (95% CI 0.69 to 1.26) | Ratio of IRR adj = 1.83; (95% CI 1.08 to 3.09) in control with intervention as reference; Men; Ratio of IRR adj = 1.29; (95% CI 0.76 to 2.19); Women; Ratio of IRR adj = 3.10; (95% CI 1.10 to 8.73) | NR | NR | NR | NR | NR | NR
Oyama 2016^41^; Observational with concurrent control | 63 suicides | 37 suicides | 59 suicides | 2005-2010:; range of rates: 35.4 to 47.6 per 100,000 per year; 65 suicides | [underlined: Intervention]; IRR adj = 0.52 (95% CI 0.33 to 0.83); [underlined: Control]; IRR adj = 0.93 (95% CI 0.69 to 1.26) | Ratio of IRR adj = 1.83; (95% CI 1.08 to 3.09) in control with intervention as reference; Men; Ratio of IRR adj = 1.29; (95% CI 0.76 to 2.19); Women; Ratio of IRR adj = 3.10; (95% CI 1.10 to 8.73) | NR | NR | NR | NR | NR | NR
Oyama 2016^41^; Observational with concurrent control | Men; 32 suicides | Men; 26 suicides | Men; 40 suicides | Men; 37 suicides | [underlined: Intervention]; IRR adj = 0.52 (95% CI 0.33 to 0.83); [underlined: Control]; IRR adj = 0.93 (95% CI 0.69 to 1.26) | Ratio of IRR adj = 1.83; (95% CI 1.08 to 3.09) in control with intervention as reference; Men; Ratio of IRR adj = 1.29; (95% CI 0.76 to 2.19); Women; Ratio of IRR adj = 3.10; (95% CI 1.10 to 8.73) | NR | NR | NR | NR | NR | NR
Oyama 2016^41^; Observational with concurrent control | Women; 31 suicides | Women; 11 suicides | Women; 22 suicides | Women; 25 suicides | [underlined: Intervention]; IRR adj = 0.52 (95% CI 0.33 to 0.83); [underlined: Control]; IRR adj = 0.93 (95% CI 0.69 to 1.26) | Ratio of IRR adj = 1.83; (95% CI 1.08 to 3.09) in control with intervention as reference; Men; Ratio of IRR adj = 1.29; (95% CI 0.76 to 2.19); Women; Ratio of IRR adj = 3.10; (95% CI 1.10 to 8.73) | NR | NR | NR | NR | NR | NR

CI=confidence interval; IRR=incident rate ratio; NR=not reported; RCT=randomized controlled trial

Appendix Table 5-47 Screening for At-Risk: Secondary Outcomes

Author, Year; Study Design | Stigma Towards Suicide | Caregiver Burden | Cost | Substitution (Alternative Method)
Wasserman 2015^32^ (SEYLE); Cluster RCT | NR | NR | NR | NR
Dezso 2018^43^; Observational with concurrent control | NR | NR | NR | NR
Oyama 2017^42^; Observational with concurrent control | NR | NR | NR | NR
Oyama 2016^41^; Observational with concurrent control | NR | NR | NR | NR

NR=not reported; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

Appendix Table 5-48 Screening for At-Risk: Strategies to Deliver, Sustain, and Improve the Quality of Intervention^*^

Author, Year; Study Design | Strategies to Deliver the Intervention | Strategies to Sustain the Intervention | Strategies to Improve the Quality of the Intervention
Wasserman 2015^32^ (SEYLE); Cluster RCT | Local teams were trained in the study methods and a steering group monitored adherence (process assessments and quality control—though limited detail given). | Embedded into school setting. | Recommended/suggested screening would be more acceptable to stakeholders if completed with concurrent activities to reduce stigma of mental health issues.; Recommended evaluation of booster activities and combination of different interventions.
Oyama 2017^42^; Observational with concurrent control | Each intervention cluster (municipality) was given a standardized work plan; Dissemination of public information (leaflets and newsletter) on depression as a risk factor for suicide, depression screening, and treatment options. This was done to improve receptiveness to depression screening which was the main element of the intervention. | NR | Recommended exploring the long-term effect of personal contact alone without the screening procedure
Oyama 2016^41^; Observational with concurrent control | Educational component was used first to enhance receptiveness to screening. | NR | NR

NR=not reported; RCT=randomized controlled trial; SEYLE=Saving and Empowering Young Lives in Europe

* We abstracted this information from studies that found an intervention to be effective (defined as yielding at least low certainty evidence on reducing suicide deaths or attempts).

Appendix Table 5-49 Multi-Strategy Programs: Study Characteristics

Author, Year; Country; Study Design; Intervention Type; Setting; Funding; Risk of Bias | Inclusion/Exclusion Criteria | Intervention; Comparator; Study Period; Length of Follow-up | Demographics
Collings 2018^44^; Country: New Zealand; Study Design: Cluster RCT; Intervention Type: Multi-strategy; Setting: General community; Funding: Government; Risk of Bias: Medium | Inclusion: The pool of 20 potential District Health Boards ranged from 31,000 to 481,00 people. Prior to randomization, District Health Boards were matched on a variety of demographic factors including age-standardized suicide rates, socioeconomic deprivation, population size, and number of full-time-equivalent general practitioners. Four pairs (8 total) were selected.; Exclusion: NR | Intervention: Multi-level intervention in 4 District Health Boards; Adapted Question, Persuade, and Refer program module was accessible online. Provided training in recognition of suicide factors and how to encourage help; Workshops on mental health issues were delivered and tailored to local needs. Workshops hosted by community health organizations Community based interventions involving advocacy and information. Included workshops to media on safe reporting; Distribution of print material and information on web-based resources; Comparator: Practice as usual; Study period: June 1, 2010 to June 1, 2012. The preceding 6 months was used for baseline data; Length of follow-up: 25 months | N=NR; Age (years, median): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Hegerl 2019^45^ (suicides and attempts); Harris 2016^71^ (implementation); Country: Germany, Hungary, Portugal, Ireland; Study Design: Observational with concurrent control; Intervention Type: Multi-strategy; Setting: Community; Funding: Government; Risk of Bias: Medium; Both articles evaluated the European Alliance Against Depression that was implemented in Germany, Hungary, Portugal, and Ireland. We used the Hegerl 2019 article to extract baseline characteristics and suicide outcomes. We used the Harris 2016 article to extract additional information about implementation. | Inclusion: Regions in 4 selected countries (Germany, Hungary, Portugal, Ireland) with at least 150,000 inhabitants, regional interest in hosting the intervention, and no previous suicide prevention or depression awareness program in the region; Exclusion: NR | Intervention: Multi-level intervention based on the 4-level European Alliance Against Depression; Primary care training; Public awareness campaign; Community facilitator training; Support for self-help groups; Plus, efforts to restrict access to lethal means by local identification and security inspection of areas where suicides occur; Note: some variation in intervention between countries; Comparator: No intervention (in regions matched on population); Study period: Unclear; reported baseline population data for 2008; Length of follow-up: 2 years | N= Populations in the intervention and control regions in 2008:; Germany: 745,516; Hungary: 339,264; Ireland: 426,197; Portugal: 338,213; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Hegerl 2010^46^; Country: Germany; Study Design: Observational with concurrent control; Intervention Type: Multi-strategy; Setting: Community; Funding: Government; Risk of Bias: Medium | Inclusion: Nuremberg and Wuerzburg regions of Germany; Exclusion: NR | Intervention: 4-level Nuremberg Alliance Against Depression; 1) training primary care physicians; 2) media and public campaign; 3) training of community facilitators; 4) support for depressed persons, suicide attempters and their families (self-help groups, emergency cards); Note: Intensive intervention stopped at the end of the 2^nd^ year (2002), with ‘minor’ interventions in follow-up year; Comparator: No intervention in the control region (Wuerzburg); Study period: 2000-2003; Length of follow-up: 1 year | N= Populations in the intervention and control region in 2000:; Nuremberg: 488,400; Wuerzburg: 287,000; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status= unemployment rate in 2000:; Nuremburg: 10.1%; Wuerzburg: 5.6%; Mental health diagnoses: NR; Prior suicide behavior: NR
Hübner-Liebermann 2010^48^; Country: Germany; Study Design: Observational with concurrent control; Intervention Type: Multi-strategy; Setting: Community; Funding: NR; Risk of Bias: Medium | Inclusion: Populations of a) city of Regensburg, b) county district of Regensburg, c) county district of Neumarkt, and d) Germany; Exclusion: NR | Intervention: 4-Level Regensburg Alliance Against Depression; 1) General Practitioner cooperation; 2) Education for general public; 3) Training workshops for secondary teachers, lay helpers, carers for elderly, police personnel, and other professionals; media guide; 4) Self-help groups and groups for relatives of those affected by depression; flyers with crisis service and hospital resources; Comparator: No intervention in control regions (2 county districts); Study period: 1998-2007; Length of follow-up: 4 years. Intervention started in 2003 | N= Populations in the intervention and control region:; City of Regensburg: 150,000; Country district Regensburg: 180,000; Country district Neumarkt: 130,000; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: 24 per 100,000 (2002, year before intervention)
Székely 2013^47^; Country: Hungary; Study Design: Observational with concurrent control; Intervention Type: Multi-strategy; Setting: Community; Funding: Government; Risk of Bias: Low | Inclusion: Southern and eastern regions of Hungary (cities of Szolnok and Szeged) and all of Hungary; Exclusion: None reported | Intervention: 4-Level European alliance Against Depression; 1) Cooperation with general practitioners; 2) Public relations campaign; 3) Training community facilitators; 4) Support high-risk groups/self-help (emergency cards with hotline number; educational materials to support telephone emergency services); Comparator: No intervention in a control city (Szeged); Study period: 2002-2007; Length of follow-up: 3 years (included 2 years during intervention phase) | N= Populations in the intervention and control region in 2004:; Szolnok: 76,881; Szeged: 162,586; Age (years, mean): NR; Gender (% male):; Szolnok: 47%; Szeged: 46%; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: unemployment rate in 2004:; Szolnok: 5.9%; Szeged: 4.7%; Mental health diagnoses: NR; Prior suicide behavior: NR
Ono 2013^49^; Country: Japan; Study Design: Observational with concurrent control; Intervention Type: Multi-strategy; Setting: General community (rural and highly population areas); Funding: Local government and local health authorities; Risk of Bias: Low | Inclusion: The entire population in 2 rural areas and 2 highly populated areas near metropolitan cities.; Exclusion: NR | Intervention: Community-based multi-modal intervention, including; Leadership involvement: a) publicizing messages from the mayor and officials b) establishment of regional committee to promote organization-wide awareness c) formalization of roles to promote pathways to build social support networks; Education and Awareness to reduce stigma and improve recognition of suicide risk and facilitate help seeking a) public health events, posters, websites, placards, leaflets b) regional educational opportunities; Gatekeeper training: community leaders, priests, telephone hotlines, social services, youth workers, geriatric care providers, policy, physicians, pharmacists, school employees; Supporting individuals at high risk a) home visits by regional public health nurses and psychiatrists b) regional social gatherings c) Screening to identify at-risk individuals d) support for self-help activities for high risk groups; Comparator: Suicide prevention activities as usual; Study period: 2003-2009; Length of follow-up: Pre- and post-intervention periods both 3.5 years | [underlined: Rural]; N=Population in 2006:; Intervention: 291,459; Control: 339,674; Age (years, mean): NR; Intervention: 16% under 25, 55% 25-64, 29% 65 and over; Control: 16% under 25, 53% 25-64, 31% 65 and over; Gender (% male):; Intervention: 47%; Control: 47%; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR; [underlined: Highly Populated]; N=Population in 2006:; Intervention: 615,586; Control: 704,341; Age (years, mean): NR; Intervention: 17% under 25, 66% 25-64, 17% 65 and over; Control: 17% under 25, 64% 25-64, 19% 65 and over; Gender (% male):; Intervention: 50%; Control: 49%; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Kato 2019^51^ (overall and subgroups by sex); Okada 2020^59^ (subgroups by age); Country: Japan; Study Design: Pre-post observational with no concurrent control; Intervention Type: Multi-strategy; Setting: General community; Funding: Government; Risk of Bias: Medium | Inclusion: Suicide rates obtained from the Ministry of Health, Labour, and Welfare and the Statistics Bureau of the Ministry of Internal Affairs and Communications of Japan; Exclusion: NR | Intervention: Emergency Fund to Enhance Community-Based Suicide Countermeasures. Components included: personal consultation support, telephone consultation, development program for leaders/listeners, enlightenment program to enhance social support for high risk persons, and an intervention model program.; Comparator: years prior to emergency funds; Study period: 2009-2018, though the funding period was 2009 and 2014; Length of follow-up: 9 years | N= Mean population of 2.7 million across the 47 prefectures in Japan; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Lee 2018^52^; Country: South Korea; Study Design: Pre-post observational with no concurrent control; Intervention Type: Multi-strategy; Setting: General community; Funding: University; Risk of Bias: Low | Inclusion: Suicide deaths coded as X60-X84 according to the ICD-10 code from Statistic Korea; Exclusion: NR | Intervention: National Suicide Prevention Program (eg, high risk group-oriented monitoring and prevention, general population mass media campaign); Comparator: pre-intervention; Study period: 1993-2016; Length of follow-up: ~13 years after the 1^st^ program. ~8 years for the 2^nd^ program | N=48,485,314 population of South Korea in 2004; Age (years): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Lai 2019^50^; Country: Hong Kong; Study Design: Observational with concurrent control; Intervention Type: Multi-strategy; Setting: General community; Funding: University, government; Risk of Bias: Medium | Inclusion: Housing estate in North district intervention site; Exclusion: NR | Intervention: A multi-strategy intervention in a high-risk housing estate in the North District universal programs: mental health events, mental health materials, limit access to suicide means;; selective programs: training workshops for gatekeepers, training for volunteers; indicated programs: referral systems, psychosocial services, resource kits; Comparator: Three other housing estates in the North District; Study period: 2006-2015; Length of follow-up: ~4 years. The program started July 1^st^, 2011 | N=NR; Age (years, mean): NR; Study site: 6% <15 years, 18% 15-24, 28% 25-44, 40% 45-64, 8% ≥65; Control site 1: 24% <15 years, 15% 15-24, 29% 25-44, 24% 45-64, 7% ≥65; Control site 2: 8% <15 years, 22% 15-24, 24% 25-44, 35% 45-64, 11% ≥65; Control site 3: 7% <15 years, 27% 15-24, 21% 25-44, 36% 45-64, 9% ≥65; Gender (% male):; Study site: 49%; Control site 1: 48% male; Control site 2: 51% male; Control site 3: 46% male; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status:; Median monthly income (US$):; Study site: 2,421; Control site 1: 1,245; Control Site 2: 2,060; Control site 3: 1,792; Mental health diagnoses: NR; Prior suicide behavior: NR
Nakanishi 2020^58^; Country: Japan; Study Design: Pre-post observational with no concurrent control; Intervention Type: Multi-strategy; Setting: General community; Funding: Government; Risk of Bias: Medium | Inclusion: Suicide data obtained from death certificates from the Ministry of Health, Labour, and Welfare; Exclusion: NR | Intervention: Suicide Prevention Act; 1. Research on prevalence, risk, and protective factors for suicide; 2. Assessment and management of suicidal behaviors; 3. Assessment and management of mental and substance use disorders; 4. Follow up and community support; 5. Crisis hotlines; 6. Gatekeeper training,; 7. Intervention for vulnerable groups; 8. Restriction to suicide means; 9. Increased public awareness and responsible media reporting; 10. Access to health care and policies to reduce harmful use of alcohol; Comparator: years before and after the Suicide Prevention Act; Study period: Data from 1996-2016 (divided into intervals surrounding a recession, suicide prevention act, and an earthquake); Length of follow-up: Trend measured for the 5 years after the intervention | N=NR (only reported among completed suicides); Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Nakanishi 2015^53^; Country: Japan; Study Design: Pre-post observational with no concurrent control; Intervention Type: Multi-strategy; Setting: General community; Funding: Government; Risk of Bias: Medium | Inclusion: Japanese local authorities in their position as of April 30, 2013; Exclusion: NR | Intervention: Five components possible including 1) face to face counseling, 2) tele counseling, 3) training of community service providers, 4) public awareness campaigns, and 5) trauma informed policies and practices. Each local authority voluntarily determines the components of the suicide prevention program to be implemented in their prefecture; this national initiative and funding was launched in 2009.; Comparator: time since 2009; Study period: 2009-2012; Length of follow-up: 3 years | N=range 24,320-175,157 (reported by intervention category); Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: annual per capita income range 1.1-1.2 million yen (reported by intervention type); Mental health diagnoses: NR; Prior suicide behavior: NR
Law 2019^54^; Country: Hong Kong; Study Design: Pre-post observational with no concurrent control; Intervention Type: Multi-strategy; Setting: General community; Funding: NR; Risk of Bias: Medium | Inclusion: NR; Exclusion: NR | Intervention: Centre for Suicide Research and Prevention applied a multi-component approach based after WHO recommendations including: 1) surveillance, 2) identifying risks and protective factors, 3) develop and evaluate interventions, and 4) implement.; Comparator: before the Centre was established; Study period: 1997-2016; Length of follow-up: ~14 years. The Centre was established in 2002 | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Lung 2017^55^; Country: Taiwan; Study Design: Pre-post observational with no concurrent control; Intervention Type: Multi-strategy; Setting: General community; Funding: None; Risk of Bias: Low | Inclusion: 9 urban and 14 rural areas in Taiwan; Exclusion: None reported | Intervention: Taiwan Suicide Prevention Center provides integrated platform for suicide prevention and control, assists county and city health bureaus and mental health network hospitals, and related suicide prevention instruments (prevention strategies, care materials, suicide risk assessment, gatekeeper training, standardizing reporting and aftercare delivery, organizing community support networks); Note: 1^st^ phase: 2005-2008; 2^nd^ phase: 2009-2013; Comparator: Pre-intervention; Study period: 1991-2013; Length of follow-up: ~9 years after 1^st^ phase. ~5 years after 2^nd^ program | N=NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Page 2011^60^; Country: Australia; Study Design: Observational with concurrent control; Intervention Type: Multi-strategy; Setting: General community; Funding: NR; Risk of Bias: Medium | Inclusion: Prevention programs/ activities clearly related to the immediate area in which the organization was based.; Exclusion: Prevention programs/activities that targeted a broader region or where it was unclear as to which geographic area the program related were not included in the primary analyses. | Intervention: National Youth Suicide Prevention Strategy (139 local areas); 1) Community and professional education activities; 2) Crisis, early intervention, treatment and referral support; 3) Counseling and personal development initiatives; 4) Health promotion initiatives; Note: exact prevention strategies may have varied by local area; Comparator: Local areas with no prevention activity (774 local areas); Study period: Period implementation (1995-1998) and the period after implementation (1999-2002).; Suicide data for 1992-1994 was used to establish suicide rate prior to implementation; Length of follow-up: up to 8 years | N=Population catchment approximately 2.3 million; Age (years, median): NR, people were aged 20-34 years; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR; Mental health diagnoses: NR; Prior suicide behavior: NR
Ross 2020^56^ (longer-term follow-up); Lockley 2014^57^ (shorter-term follow-up); Country: Australia; Study Design: Pre-post observational with no concurrent control; Intervention Type: Multi-strategy; Setting: Suicide hotspot; Funding: Government and local councils; Risk of Bias: Medium | Inclusion: Data from the National Coronial Information System for closed cases by the coroner where a suicide occurred for 2000-2016 within postcode 2030. Also, data on cases that occurred within Gap Park Masterplan area.; Exclusion: None | Intervention: Multi-strategy at Gap Park in Sydney, Australia.; Means restriction: construction of 130-centimeter fencing along the cliff-tops.; Encourage help-seeking: installation of 2 crisis telephones and 2 signs to encourage help-seeking.; Increase likelihood of intervention by a third party: installation of cameras to record footage and assist in real-time and landscaping work to increase the probability that people would be present; Comparator: Pre-intervention; Study period: 2000-2016; Length of follow-up: 10-year pre-intervention, 2-year implementation period, 5-year post-intervention | N= NR; Age (years, mean): NR; Gender (% male): NR; Race (%): NR; Military status: NR; Housing status: NR; Socioeconomic status: NR (employment status only reported among completed suicides); Mental health diagnoses: NR; Prior suicide behavior: NR

ICD-10 International Classification of Diseases; NR=not reported; RCT=randomized controlled trial; WHO=World Health Organization

Appendix Table 5-50 Multi-Strategy Programs: Risk of bias – Cluster RCTs

Author, Year | Sequence Generation | Allocation Concealment | Recruitment Bias | Baseline Imbalance | Blinded Outcome Assessment | Incomplete Cluster Data | Incomplete Outcome Data | Selective Outcome Reporting | Overall Risk of Bias
Collings 2018^44^ | Low (computer-generated) | Low (independent statistician) | Low (recruitment prior to randomization) | Unclear (reported matching on a variety of demographic factors) | Low (suicide the only outcome, data obtained from coroner services) | Low | Unclear (no information) | Low | Low

RCT=randomized controlled trial

Appendix Table 5-51 Multi-Strategy Programs: Risk of Bias – Non-RCTs^*^

Author, Year | Did the study include all eligible participants or were the participants a representative sample from the population of interest? | Were the participants included in any comparison similar? | Were the participants included in any comparisons receiving similar treatment/ care, other than the exposure or intervention of interest? | Was the control group concurrent? | For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/ exposure? | Was follow-up complete? | Was completeness of follow-up similar for study groups? | Were the outcomes of participants included in any comparisons measured in the same way? | Were suicide deaths and/or attempts measured in a reliable way? | Were other eligible outcomes measured in a reliable way? | Did the study adjust for confounding variables? | Overall Risk of Bias
Hegerl 2019^45^; Harris 2016^71^ | Yes | Unclear | Unclear | Yes | NA | Yes | Yes | Yes | No (for attempts) | NA | Unclear | Medium
Hegerl 2010^46^ | Yes | Unclear | Unclear | Yes | No | Yes | Yes | Yes | Unclear (attempts) | NA | No | Medium
Hübner-Liebermann 2010^48^ | Yes | Unclear | Unclear | Yes | Yes | Unclear | Unclear | Unclear | Unclear | NA | No | Medium
Székely 2013^47^ | Yes | Unclear | Unclear | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | Low
Ono 2013^49^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | Low
Kato 2019^51^; Okada 2020^59^ | Yes | Unclear | Unclear | No | Yes | Unclear | Unclear | Yes | Yes | NA | Yes | Medium
Lee 2018^52^ | Yes | Yes | Unclear | NA | Yes | NA | Unclear | Yes | Yes | NA | Yes | Low
Lai 2019^50^ | Yes | Yes | Yes | Yes | Yes | NA | Unclear | Yes | Yes | NA | No | Medium
Nakanishi 2020^58^ | Yes | Yes | Unclear | No | Yes | NA | NA | Yes | Yes | NA | Yes | Medium
Nakanishi 2015^53^ | Yes | Unclear | Unclear | Yes | NA | NA | NA | Yes | Yes | NA | Yes | Medium
Law 2019^54^ | Yes | Unclear | Unclear | No | Yes | NA | NA | NA | Yes | NA | No | Medium
Lung 2017^55^ | Yes | Unclear | Unclear | Yes | Yes | NA | NA | Yes | Yes | NA | Yes | Low
Page 2011^60^ | Yes | Yes | Unclear | Yes | No | NA | NA | Yes | Yes | NA | Yes | Medium
Ross 2020^56^; Lockley 2014^57^ | Yes | Unclear | Unclear | No | Yes | NA | NA | Yes | Yes | Unclear (costs) | No | Medium
Wang 2013^81^ | Unclear | No | Unclear | No | No | Yes | Yes | Yes | Unclear | NA | No | High
King 2011^82^ | Unclear | Yes | NA | No | No | No | NA | Yes | Unclear | NA | No | High
Nakanishi 2017^83^ | Yes | No | Unclear | Yes | NA | Unclear | Unclear | Yes | Yes | NA | Yes | High
Pirrucello 2010^84^ | Unclear | Unclear | Unclear | NA | No | NA | Unclear | Yes | Unclear | No | No | High
Matsubayashi 2011^85^ | Yes | No | Unclear | No | NA | NA | NA | Yes | Unclear | NA | No | High

* Modification of the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies

NA=not applicable; RCT=randomized controlled trial

Appendix Table 5-52 Multi-Strategy Programs: Suicide Deaths and Attempts from RCTs

Author, Year; Study Design | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study Design | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study Design | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Collings 2018^44^; Cluster RCT | District A; Baseline: 13 deaths; District B; Baseline: 11 deaths; District C; Baseline: 10 deaths; District D; Baseline: 6 deaths | District A; 25 months: 33 deaths; District B; 25 months: 53 deaths; District C; 25 months: 64 deaths; District D; 25 months: 46 deaths | District A; Baseline: 13 deaths; District B; Baseline: 21 deaths; District C; Baseline: 11 deaths; District D; Baseline: 24 deaths | District A; 25 months: 61 deaths; District B; 25 months: 68 deaths; District C; 25 months: 49 deaths; District D; 25 months: 111 deaths | [underlined: Intervention]; Rate ratio = 1.17 (95% CI 0.84 to 1.65); [underlined: Control]; Rate ratio = 1.01 (95% CI 0.77 to 1.31) | Intervention effect ratio; = 1.18; (95% CI 0.51 to 2.70) | NR | NR | NR | NR | NR | NR

CI=confidence interval; NR=not reported; RCT=randomized controlled trial

Appendix Table 5-53 Multi-Strategy Programs: Suicide Deaths and Attempts from Non-RCTs with Concurrent Control

Author, Year; Study Design | Suicide Deaths | | | | | | Suicide Attempts
Author, Year; Study Design | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control | Intervention Group | | Control Group | | Pre vs Post | Intervention vs Control
Author, Year; Study Design | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control | Pre | Post | Pre | Post | Pre vs Post | Intervention vs Control
Hegerl 2019^45^; Harris 2016^71^; Observational with concurrent control | All regions; 138 suicides | All regions; 2 years:; Mean (SD) 163 (13) suicides | All regions; 88 suicides | All regions; 2 years:; Mean (SD) 112 (4) suicides | [underlined: Intervention]; +18.1% from baseline; [underlined: Control]; +27.3% from baseline | OR= 0.93 (95% CI 0.65 to 1.33) | All regions; 1,643 attempts | All regions; 2-years:; Mean (SD) 1,545 (178) attempts | All regions; 1,195 attempts | All regions; 2-years:; Mean (SD) 1,128 (112) attempts | [underlined: Intervention]; −6.0% from baseline; [underlined: Control]; −5.6% from baseline | OR= 1.00 (95% CI 0.90 to 1.11)
Hegerl 2010^46^; Observational with concurrent control | Nuremberg; 100 suicides | Nuremberg; Follow-up year:; 88 suicides | Wuerzburg; 58 suicides | Wuerzburg; Follow-up year:; 42 suicides | NR | NR | Nuremberg; 520 attempts | Nuremberg; Follow-up year:; 331 attempts | Wuerzburg; 125 attempts | Wuerzburg; Follow-up year:; 131 attempts | [underlined: Intervention]; baseline −36.2% from baseline; [underlined: Control]; +4.8% from baseline | P=.0005 vs control during same time period
Székely 2013^47^; Observational with concurrent control | Szolnok; 2002-2004:; 30.0 per 100,000; Men; 45.5 per 100,000; Women; 16.3 per 100,000 | Szolnok; 2005-2007:; 13.2 per 100,000; Men; 18.0 per 100,000; Women; 9.1 per 100,000 | Szeged; 2002-2004:; 26.2 per 100,000; Men; 41.3 per 100,000; Women; 13.3 per 100,000 | Szeged; 2005-2007:; 26.7 per 100,000; Men; 43.5 per 100,000; Women; 12.4 per 100,000 | [underlined: Intervention]; −55.9% mean change Cohen’s d: 8.30; Men; −60.5% Cohen’s d: 5.53; Women; −44.3%; Cohen’s d: 3.19; [underlined: Control]; Szeged +2% Cohen’s d: 0.15; Men; +5.4% Cohen’s d: 0.31; Women; −6.3% Cohen’s d: 0.28; All of Hungary; −9.6% Cohen’s d: 3.72; Men; −9.9% Cohen’s d: 2.94; Women; −8.7% Cohen’s d: 4.78 | NR | NR | NR | NR | NR | NR | NR
Székely 2013^47^; Observational with concurrent control | | | All of Hungary; 2002-2004:; 27.6 per 100,000; Men; 44.6 per 100,000; Women; 12.2 per 100,000 | All of Hungary; 2005-2007:; 24.9 per 100,000; Men; 40.2 per 100,000; Women; 11.1 per 100,000 | | NR | NR | NR | NR | NR | NR | NR
Hübner-Liebermann 2010^48^; Observational with concurrent control | City of Regensburg; 1998:; 21 per 100,000; 2003:; 13 per 100,000 | City of Regensburg; 2004:; 7 per 100,000; 2007:; 14 per 100,000 | County of Regensburg; 1998:; 19 per 100,000; 2003:; 13 per 100,000 | County of Regensburg; 2004:; 9 per 100,000; 2007:; 11 per 100,000 | City of Regensburg; Males; Significant change in male suicide rate; P<=.001; Females; No change in female suicide rate; P=.28 | NR | NR | NR | NR | NR | NR | NR
Hübner-Liebermann 2010^48^; Observational with concurrent control | | | County of Neumarkt; 1998:; 10 per 100,000; 2003:; 7 per 100,000 | County of Neumarkt; 2004:; 9 per 100,000; 2007:; 13 per 100,000 | City of Regensburg; Males; Significant change in male suicide rate; P<=.001; Females; No change in female suicide rate; P=.28 | NR | NR | NR | NR | NR | NR | NR
Hübner-Liebermann 2010^48^; Observational with concurrent control | | | Germany overall; 1998:; 14 per 100,000; 2003:; 14 per 100,000 | Germany overall; 2004:; 13 per 100,000; 2007:; 11 per 100,000 | City of Regensburg; Males; Significant change in male suicide rate; P<=.001; Females; No change in female suicide rate; P=.28 | NR | NR | NR | NR | NR | NR | NR
Ono 2013^49^; Observational with concurrent control | Rural; 46.6 per 100,000 | Rural; 38.2 per 100,000 | Rural; 40.6 per 100,000 | Rural; 38.8 per 100,000 | NR | Rural; 3.5 years RR 1.09 (95% CI 0.82 to 1.45); Females; RR 1.44 (95% CI 0.85 to 2.43); RRs for other subgroups only in graph; not significantly different; Highly populate; RRs only in graph. Not significantly different except decrease in females | Rural; 24.8 per 100,000 | Rural; 18.8 per 100,000 | Rural; 26.0 per 100,000 | Rural; 23.8 per 100,000 | NR | Rural; 3.5 years; RR 0.86 (95% CI 0.55 to 1.36); Females; RR 1.56 (95% CI 0.80 to 3.04); Males; RR 0.39 (95% CI 0.22 to 0.68); <25 years; RR 0.74 (95% CI 0.24 to 2.31); 25-65 years; RR only in graph. Not significantly different; >65 years; RR 0.35 (95% CI 0.17 to 0.71); Highly Populate; RRs only in graph. Not significantly different except decrease in males and increase in females
Ono 2013^49^; Observational with concurrent control | Highly populate; 22.8 per 100,000; Note: rates calc by review team | Highly populate; 23.2 per 100,000 | Highly populate; 26.0 per 100,000 | Highly populate; 24.8 per 100,000 | NR | | Highly populate; 24.0 per 100,000; Note: rates calc by review team | Highly populate; 29.0 per 100,000 | Highly populate; 26.6per 100,000 | Highly populate; 32.8 per 100,000 | NR
Lai 2019^50^; Observational with concurrent control | Intervention Site; 2006-2010:; 16 suicides | Intervention Site; 2012-2015:; 11 suicides; Note: program started in July 2011 | Control Site 1; 2006-2010:; 3 suicides | Control Site 1; 2012-2015:; 6 suicides | Intervention Site; Trend from 2010-2015:; P>.001 | NR | NR | NR | NR | NR | NR | NR
Lai 2019^50^; Observational with concurrent control | Intervention Site; 2006-2010:; 16 suicides | Intervention Site; 2012-2015:; 11 suicides; Note: program started in July 2011 | Control Site 2; 2006-2010:; 5 suicides | Control Site 2; 2012-2015:; 6 suicides | Control Site 1; Trend from 2010-2015:; P=.172 | NR | NR | NR | NR | NR | NR | NR
Lai 2019^50^; Observational with concurrent control | Intervention Site; 2006-2010:; 16 suicides | Intervention Site; 2012-2015:; 11 suicides; Note: program started in July 2011 | Control Site 3; 2006-2010:; 3 suicides | Control Site 3; 2012-2015:; 3 suicides | Control Site 2; Trend from 2010-2015:; P=1 | NR | NR | NR | NR | NR | NR | NR
Lai 2019^50^; Observational with concurrent control | Intervention Site; 2006-2010:; 16 suicides | Intervention Site; 2012-2015:; 11 suicides; Note: program started in July 2011 | | | Control Site 3; Trend from 2010-2015:; P=.325 | NR | NR | NR | NR | NR | NR | NR
Page 2011^60^; Observational with concurrent control | Baseline 1992-1994:; Men; 32.7 per 100,000; Women; 4.4 per 100,000; Period of activity 1995-1998:; Men; 37.4 per 100,000; Women; 7.7 per 100,000 | 1999-2002:; Men; 33.7 per 100,000; Women; 8.1 per 100,000; [underlined: Change in] [underlined: rates over] [underlined: 1999-2002]; Men; 12.5% (95% CI, −22.5 to −1.3); Women; 8.1% (95% CI, −14.3 to 36.4) | Baseline 1992-1994:; Men; 33.3 per 100,000; Women; 6.0 per 100,000; Period of activity 1995-1998:; Men; 39.4 per 100,000; Women; 6.4 per 100,000 | 1999-2002:; Men; 35.2 per 100,000; Women; 7.2 per 100,000; [underlined: Change in] [underlined: rates over] [underlined: 1999-2002]; Men; −7.9% (95% CI, −15.9 to 0.7); Women; 11.5% (95% CI, −9.3 to 37.1) | 1995-1998:; Men; RR adjusted 0.95 (95% CI, 0.85 to 1.06); 1999-2002:; RR adjusted 0.96 (95% CI, 0.86 to 1.07); 1995-1998:; Women; RR adjusted 1.20 (95% CI, 0.94 to 1.52); 1999-2002:; RR adjusted 1.12 (95% CI, 0.90 to 1.40) | [underlined: Difference in] [underlined: change in] [underlined: rates 1999-2002:]; Men; P=.541; Women; P=.770 | NR | NR | NR | NR | NR | NR

CI=confidence interval; NR=not reported; OR=odds ratio; RCT=randomized controlled trial; RR=rate ratios (for Ono 2013 study) and relative risk (for Page 2011 study); SD=standard deviation

Appendix Table 5-54 Multi-Strategy Programs: Suicide Deaths and Attempts from Non-RCTs with No Concurrent Control

Author, Year; Study Design | Suicide Deaths | | | Suicide Attempts
Author, Year; Study Design | Pre-Intervention | Post-Intervention | Pre vs Post Comparison | Pre-Intervention | Post-Intervention | Pre vs Post Comparison
Kato 2019^51^; Okada 2020^59^; Pre-post observational with no concurrent control | 2009:; 25.7 suicides per 100,000 | 2018:; 16.5 suicides per 100,000 | As reported in the Kato 2019 article; Time dependent reduction trends on all persons (mean ±SD):; −1.15 ±0.26; Change from 2009 to 2018: P<.05 for all prefectures; Decreases associated with enlightenment program and development of leader and listener; Males; Time dependent reduction trends (mean ±SD):; −1.74 ±0.43; Change from 2009 to 2018: P<.05 for all prefectures; Decreases associated with enlightenment program and intervention model. Increase associated with personal consultation program; Females; Time dependent reduction trends (mean ±SD):; −0.61 ±0.18; Change from 2009 to 2018: P<.05 in all but 2 prefectures; Decrease associated with development of leader and listener; As reported in the Okada 2020 article; Age 20-29; Decrease with telephone consultation support and enlightenment program. Increase with development program of leaders and listeners; Age 30-39; Decrease with intervention model program and enlightenment program; Age 40-49; No differences; Age 50-59; Decrease with enlightenment program. Increase with personal consultation program; Age 60-69; Decrease with intervention model program and enlightenment program. Increase with personal consultation program; Age 70-79; Decrease with enlightenment program and telephone consultation; Age 80+; Decrease with personal consultation program, enlightenment program, and intervention model program | NR | NR | NR
Lee 2018^52^; Pre-post observational with no concurrent control | 1993-2003; 14.9 per 100,000 (calculated by investigators) | 2004-2016; 27.2 per 100,000 (calculated by investigators); 1^st^ strategy; 2004-2008; 24.2 per 100,000 (calculated by investigators); 2^nd^ Strategy; 2009-2016; 28.8 per 100,000 (calculated by investigators) | 1^st^ strategy; Suicide rate from 1993-2010 increased by 5.6% annually (95% CI, 4.4 to 6.9%); 2^nd^ strategy; Suicide rate from 2010 to 2016 decreased by 5.5% annually (95% CI, −10.3 to −0.5%) | NR | NR | NR
Lee 2018^52^; Pre-post observational with no concurrent control | Males; 1993-2010:; +5.0% annually; (95% CI, 3.6 to 6.4%); Females; 1993-2009:; +7.5% annually; (95% CI, 6.3 to 8.7%) | Males; 2011-2016:; −4.3% annually; (95% CI, −9.8, 1.6%); Females; 2010-2016:; −6.1% annually (95% CI, −9.1 to −3.0%) | 1^st^ strategy; Suicide rate from 1993-2010 increased by 5.6% annually (95% CI, 4.4 to 6.9%); 2^nd^ strategy; Suicide rate from 2010 to 2016 decreased by 5.5% annually (95% CI, −10.3 to −0.5%) | NR | NR | NR
Nakanishi 2020^58^; Pre-post observational with no concurrent control | 1998-2006 (economic recession); Trend; −0.0007; (95% CI, −0.002 to 0.0008); Male; Trend; −0.0007; (95% CI, −0.003 to 0.001); Female; Trend; −0.001; (95% CI, −0.002 to 0.000); Age ≤19 years; Trend; −0.0003; (95% CI, −0.001 to 0.0002); Age 20-39 years; Trend; 0.002; (95% CI, 0.001 to 0.004); Age 40-59 years; Trend; −0.001; (95% CI, −0.004 to 0.001); Age ≤60 years; Trend; −0.002; (95% CI, −0.003 to −0.002) | 2006-2011 (Post Suicide Prevention Act); Trend; −0.001; (95% CI, −0.003 to 0.001); Male; Trend; −0.002; (95% CI, −0.006 to 0.002); Female; Trend; −0.001; (95%CI −0.002 to −0.000); Age ≤19 years; Trend; −0.0004; (95% CI, −0.001 to −0.0001); Age 20-39 years; Trend; 0.001; (95% CI, −0.002 to 0.004); Age 40-59 years; Trend; −0.004; (95% CI, −0.008 to 0.001); Age ≤60 years; Trend; −0.002; (95% CI, −0.002 to −0.001) | Trend Difference (Suicide Prevention Act); −0.0004; (95% CI, −0.003 to 0.002); Male; −0.001; (95% CI, −0.005 to 0.004); Female; 0.00008; (95%CI −0.001 to 0.001); Age ≤19 years; −0.0001; (95% CI, −0.001 to 0.001); Age 20-39 years; −0.001; (95% CI, −0.005 to 0.002); Age 40-59 years; −0.091; (95% CI, −0.268 to 0.085); Age ≤60 years; 0.001; (95% CI, −0.0001 to 0.002) | NR | NR | NR
Nakanishi 2015^53^; Pre-post observational with no concurrent control | The number of suicide cases was not significantly different between the categories of implementation of suicide-prevention programs | | | NR | NR | NR
Law 2019^54^; Pre-post observational with no concurrent control | 1997:; 10.2 per 100,000 persons; 2002:; 13.4 per 100,000 persons; Notes: rates were age-standardized | 2003:; 14.7 per 100,000 persons; 2009 (6-year follow-up):; 10.3 per 100,000 persons; 2016 (13-year follow-up):; 8.9 per 100,000 persons | NR | NR | NR | NR
Lung 2017^55^; Pre-post observational with no concurrent control | Age 15-25 years; 2004:; 6 per 100,000 persons; Age 24-44 years; 2004:; 18 per 100,000 persons; Age 45-64 years; 2004:; 22 per 100,000 persons; Age 65+ years; 2004:; 36.5 per 100,000 persons; Note: data estimated from plots | Age 15-24 years; 2008:; 6 per 100,000 persons; 2013:; 5 per 100,000 persons; Age 24-44 years; 2008:; 21.5 per 100,000 persons; 2013:; 15 per 100,000 persons; Age 45-64 years; 2008:; 24 per 100,000 persons; 2013:; 19.5 per 100,000 persons; Age 65+ years; 2008:; 36.5 per 100,000 persons; 2013:; 32 per 100,000 persons | NR | NR | NR | NR
Ross 2020^56^; Lockley 2014^57^; Pre-post observational with no concurrent control | At Gap Park; 2000-2009:; 41 suicides; Males; 22 suicides; Females; 19 suicides | At Gap Park; 2012-2016; post-intervention:; 24 suicides; Males; 16 suicides; Females; 8 suicides; 2010-2011 during implementation:; 21 suicides; Males; 10 suicides; Females; 11 suicides | At Gap Park; 2000-2016:; APC = 5.41% (95% CI, −0.38 to 11.53); Males; 2000-2016:; APC = 6.23% (95% CI, −0.41 to 13.30); Females; 2000-2010:; APC = 16.64% (95% CI, 8.18 to 25.76); 2010-2016:; APC = −21.27% (95% CI, −33.14 to −7.30) | NR | NR | NR

APC=annual percentage change; CI=confidence interval; NR=not reported; RCT=randomized controlled trial; SD=standard deviation

Appendix Table 5-55 Multi-Strategy Programs: Secondary Outcomes

Author, Year; Study Design | Stigma Towards Suicide | Caregiver Burden | Cost | Substitution (Alternative Method)
Collings 2018^44^; Cluster RCT | NR | NR | NR | NR
Hegerl 2019^45^; Harris 2016^71^; Observational with concurrent control | NR | NR | NR | NR
Hegerl 2010^46^; Observational with concurrent control | NR | NR | NR | NR
Hübner-Liebermann 2010^48^; Observational with concurrent control | NR | NR | NR | NR
Székely 2013^47^; Observational with concurrent control | NR | NR | NR | NR
Ono 2013^49^; Observational with concurrent control | NR | NR | NR | NR
Kato 2019^51^; Okada 2020^59^; Pre-post observational with no concurrent control | NR | NR | NR | NR
Lee 2018^52^; Pre-post observational with no concurrent control | NR | NR | NR | NR
Lai 2019^50^; Observational with concurrent control | NR | NR | NR | NR
Nakanishi 2020^58^; Pre-post observational with no concurrent control | NR | NR | NR | NR
Nakanishi 2015^53^; Pre-post observational with no concurrent control | NR | NR | NR | NR
Law 2019^54^; Pre-post observational with no concurrent control | NR | NR | NR | NR
Lung 2017^55^; Pre-post observational with no concurrent control | NR | NR | NR | NR
Page 2011^60^; Observational with concurrent control | NR | NR | $76 million in Australian dollars total funds for prevention programs and activities; .; Effect of level of funding on suicide rates noted | NR
Ross 2020^56^; Lockley 2014^57^; Pre-post observational with no concurrent control | NR | NR | Woollahra Council contributed $700,000 of its own funds.; [underlined: Timeline of funding]; January 2009: Woollahra Council received $248,000 which is allocated to camera installation; December 2009: $91,000 allocated under Round 2 of an infrastructure program; July 2010: $277 million pledged to initiatives to prevent suicide including at the Gap in Sydney; August 2010: If elected, Liberal-National Coalition will provide $2.1 to complete the Gap Masterplan; September 2010: Labor Government will provide $1.1 million to Woollahra Municipal Council for infrastructure; November 2010: $91,000 allocated under Round 3 of an infrastructure program; June 2012:; Successful application for $477,869 for Phase 3 of Masterplan | NR

NR=not reported; RCT=randomized controlled trial

Appendix Table 5-56 Multi-Strategy Programs: Strategies to Deliver, Sustain, and Improve the Quality of Intervention^*^

Author, Year; Study Design | Strategies to Deliver the Intervention | Strategies to Sustain the Intervention | Strategies to Improve the Quality of the Intervention
Hegerl 2019^45^; Harris 2016^71^; Observational with concurrent control | As reported in Hegerl 2019; Employ a multi-strategy approach; Engage a broad range of stakeholders; Conduct qualitative interviews/focus groups with stakeholders throughout the implementation process to identify barriers and facilitators to implementation and contextual factors influencing implementation; Conduct workshops to optimize implementation approach (fidelity); Tailor strategies for engagement and implementation to specific region context/needs; Engage local champions for healthcare provider adoption | As reported in Hegerl 2019; Provide stakeholder workshops at the end of the intervention period to reflect on sustainability and explore lessons learned; Provide training for healthcare providers that is accredited for Continuing Medical Education credits; Employ the train the trainer model for community facilitators; Develop local collaborative networks with individuals or organizational with a shared goal of reducing suicidal behavior | As reported in Hegerl 2019; Simultaneous implementation with a public mental health awareness campaign
Hegerl 2019^45^; Harris 2016^71^; Observational with concurrent control | As reported in Harris 2016; Employ a multi-strategy approach; Invite media to public launch event to engage early in the process for subsequent coverage; Engage volunteers to support the implementation capacity and dissemination | As reported in Harris 2016; Support community volunteers (initial members of self-help groups) in taking ownership of public campaigns (provide materials for distribution, give opportunities to speak at public events, listen to their ideas for dissemination); Use the program activities to create an impetus and environment for different stakeholder groups to communicate and work towards a common goal of reducing suicides | As reported in Harris 2016; Explore the value of external activities that are stimulated by association with the suicide prevention program (eg, broad training may prompt systems or facilities to start their own training programs on suicide prevention due to greater awareness)
Hegerl 2010^46^; Observational with concurrent control | NR | Follow-up year to the 2-year resource intensive intervention consisted of low-resource interventions including a depression day to increase awareness, self-help activities, and lectures about depressive disorders | NR
Hübner-Liebermann; 2010^48^; Observational with concurrent control | Employ a multi-strategy approach; Engage and collaborate with local media; Conduct training workshops for community facilitators; Distribute educational materials in multiple formats/medias to the public | Provide training for healthcare providers that is accredited for Continuing Medical Education credits | NR
Székely 2013^47^; Observational with concurrent control | Provide interactive educational packages included panel/roundtable discussions and an online information center were provided to general practitioners; Distribute educational materials in multiple formats/medias to the public; Engage and collaborate with local media; Conduct training workshops for community facilitators; Create of a local information data network to facilitate fast communication regarding high-risk persons | NR | Future research should assess health behavior (eg, alcohol and psychoactive agent use)

NR=not reported

* We abstracted this information from studies that found an intervention to be effective (defined as yielding at least low certainty evidence on reducing suicide deaths or attempts).