# APPENDIX 4 ELIGIBLE REFERENCES

Chen YY, Chen F, Chang SS, Wong J, Yip PS. Assessing the Efficacy of Restricting Access to Barbecue Charcoal for Suicide Prevention in Taiwan: A Community-Based Intervention Trial. PLoS One. 2015;10(8):e0133809.26305374
Chung YW, Kang SJ, Matsubayashi T, Sawada Y, Ueda M. The effectiveness of platform screen doors for the prevention of subway suicides in South Korea. J Affect Disord. 2016;194:80–83.26803779
Collings S, Jenkin G, Stanley J, McKenzie S, Hatcher S. Preventing suicidal behaviours with a multilevel intervention: a cluster randomised controlled trial. BMC Public Health. 2018;18(1):140.29338723
Dezso D, Konrad N, Seewald K, Opitz-Welke A. Implementation of a Suicide Risk Screening Instrument in a Remand Prison Service in Berlin. Front Psychiatry. 2018;9:665.30618858
Doran CM, Ling R, Gullestrup J, Swannell S, Milner A. The Impact of a Suicide Prevention Strategy on Reducing the Economic Cost of Suicide in the New South Wales Construction Industry. Crisis. 2016;37(2):121–129.26695869
Dueweke AR, Bridges AJ. The effects of brief, passive psychoeducation on suicide literacy, stigma, and attitudes toward help-seeking among Latino immigrants living in the United States. Stigma and Health. 2017;2(1):28–42.
Finney EJ, Buser SJ, Schwartz J, Archibald L, Swanson R. Suicide prevention in fire service: The Houston Fire Department (HFD) model. Aggression and Violent Behavior. 2015;21:1–4.
Freedenthal S. Adolescent help-seeking and the Yellow Ribbon Suicide Prevention Program: an evaluation. Suicide Life Threat Behav. 2010;40(6):628–639.21198332
Garraza L, Boyce S, Walrath C, Goldston DB, McKeon R. An economic evaluation of the Garrett Lee Smith memorial suicide prevention program. Suicide and Life-Threatening Behavior. 2018;48(1):3–11.27982449
Garraza L, Kuiper N, Goldston D, McKeon R, Walrath C. Long-term impact of the Garrett Lee Smith Youth Suicide Prevention Program on youth suicide mortality, 2006–2015. Journal of Child Psychology and Psychiatry. 2019;60(10):1142–1147.31066462
Garraza L, Walrath C, Goldston DB, Reid H, McKeon R. Effect of the Garrett Lee Smith memorial suicide prevention program on suicide attempts among youths. JAMA psychiatry. 2015;72(11):1143–9.26465226
Gravesteijn C, Diekstra R, Sklad M, de Winter M. The Effects of a Dutch School-Based Social and Emotional Learning Programme (SEL) on Suicidality in Adolescents. International Journal of Mental Health Promotion. 2011;13(4):4–16.
Han J, Batterham PJ, Calear AL, Wu Y, Xue J, Spijker BAJv. Development and pilot evaluation of an online psychoeducational program for suicide prevention among university students: A randomised controlled trial. Internet Interventions. 2018;12:111–120.30135775
Harris F, Maxwell M, O’Connor R, . Exploring synergistic interactions and catalysts in complex interventions: longitudinal, mixed methods case studies of an optimised multi-level suicide prevention intervention in 4 European countries (Ospi-Europe). BMC Public Health. 2016; 16(1):268.26979461
Hemmer A, Meier P, Reisch T. Comparing Different Suicide Prevention Measures at Bridges and Buildings: Lessons We Have Learned from a National Survey in Switzerland. PLoS One. 2017;12(1):e0169625.28060950
Hegerl U, Maxwell M, Harris F, . Prevention of suicidal behaviour: Results of a controlled community-based intervention study in 4 European countries. PLoS One. 2019;14(11):e0224602.31710620
Hegerl U, Mergl R, Havers I, . Sustainable effects on suicidality were found for the Nuremberg alliance against depression. Eur Arch Psychiatry Clin Neurosci. 2010;260(5):401–406.19921299
Hubner-Liebermann B, Neuner T, Hegerl U, Hajak G, Spiessl H. Reducing suicides through an alliance against depression? Gen Hosp Psychiatry. 2010;32(5):514–518.20851273
Ichikawa M, Inada H, Kumeji M. Reconsidering the effects of blue-light installation for prevention of railway suicides. J Affect Disord. 2014;152–154:183–185.
Jacobson JM, Osteen PJ, Sharpe TL, Pastoor JB. Randomized Trial of Suicide Gatekeeper Training for Social Work Students. Research on Social Work Practice. 2012;22(3):270–281.
Jo SJ, Yun MI, Lee MS. Effects of a province-based strategy to prevent suicide using charcoal burning: A preliminary time series analysis. Psychiatry Investigation. 2019;16(8):621–624.31446687
Kato R, Okada M. Can Financial Support Reduce Suicide Mortality Rates? Int J Environ Res Public Health. 2019;16(23):29.
Kennedy AJ, Brumby SA, Versace VL, Brumby-Rendell T. The ripple effect: a digital intervention to reduce suicide stigma among farming men. BMC public health. 2020;20:1–2.31898494
King KA, Strunk CM, Sorter MT. Preliminary effectiveness of surviving the teens((R)) suicide prevention and depression awareness program on adolescents’ suicidality and self-efficacy in performing help-seeking behaviors. J Sch Health. 2011;81(9):581–590.21831072
Knox KL, Pflanz S, Talcott GW, . The US Air Force suicide prevention program: implications for public health policy. Am J Public Health. 2010;100(12):2457–2463.20466973
Lai CCS, Law YW, Shum AKY, Ip FWL, Yip PSF. A Community-Based Response to a Suicide Cluster. Crisis. 2020;41(3):163–171.31418310
Law CK, Sveticic J, De Leo D. Restricting access to a suicide hotspot does not shift the problem to another location. An experiment of 2 river bridges in Brisbane, Australia. Aust N Z J Public Health. 2014;38(2):134–138.24690051
Law YW, Yeung TL, Ip FWL, Yip PSF. Evidence-Based Suicide Prevention: Collective Impact of Engagement with Community Stakeholders. J Evid Based Soc Work (2019). 2019;16(2):1–17.
Law CK, Yip PS. An economic evaluation of setting up physical barriers in railway stations for preventing railway injury: evidence from Hong Kong. J Epidemiol Community Health. 2011;65(10):915–920.21282146
Lee SU, Park JI, Lee S, Oh IH, Choi JM, Oh CM. Changing trends in suicide rates in South Korea from 1993 to 2016: a descriptive study. BMJ Open. 2018;8(9):e023144.
Lockley A, Cheung YT, Cox G, . Preventing suicide at suicide hotspots: a case study from Australia. Suicide Life Threat Behav. 2014;44(4):392–407.25250406
Lung FW, Liao SC, Wu CY, Lee MB. The effectiveness of suicide prevention programmes: urban and gender disparity in age-specific suicide rates in a Taiwanese population. Public Health. 2017;147:136–143.28404489
Matsubayashi T, Sawada Y, Ueda M. Does the installation of blue lights on train platforms prevent suicide? A before-and-after observational study from Japan. J Affect Disord. 2013;147(1–3):385–388.22980401
Matsubayashi T, Sawada Y, Ueda M. Does the installation of blue Lights on train platforms shift suicide to another station?: Evidence from Japan. J Affect Disord. 2014;169:57–60.25151192
Matsubayashi T, Ueda M. The effect of national suicide prevention programs on suicide rates in 21 OECD nations. Soc Sci Med. 2011;73(9):1395–1400.21940085
Matsubayashi T, Ueda M, Sawada Y. The effect of public awareness campaigns on suicides: evidence from Nagoya, Japan. J Affect Disord. 2014;152–154:526–529.
Milner A, Aitken Z, Law PCF, . The relationship between an electronic mental health stigma campaign and suicidal thoughts and behaviours: a two-arm randomized controlled trial in the Australian construction industry. Health promotion international. 2019;12.
Mishara BL, Martin N. Effects of a comprehensive police suicide prevention program. Crisis. 2012;33(3):162–168.22450038
Montgomery AE, Dichter M, Byrne T, Blosnich J. Intervention to address homelessness and all-cause and suicide mortality among unstably housed US Veterans, 2012–2016. J Epidemiol Community Health. 2020.
Nakanishi M, Endo K. National Suicide Prevention, Local Mental Health Resources, and Suicide Rates in Japan. Crisis. 2017;38(6):384–392.28748710
Nakanishi M, Endo K, Ando S, Nishida A. The Impact of Suicide Prevention Act (2006) on Suicides in Japan: An interruped time-series analysis. Crisis: The Journal of Crisis Intervention and Suicide Prevention. 2020;41(1):24–31.
Nakanishi M, Yamauchi T, Takeshima T. National strategy for suicide prevention in Japan: impact of a national fund on progress of developing systems for suicide prevention and implementing initiatives among local authorities. Psychiatry Clin Neurosci. 2015;69(1):55–64.25041482
Okada M, Hasegawa T, Kato R, Shiroyama T. Analysing regional unemployment rates, GDP per capita and financial support for regional suicide prevention programme on suicide mortality in Japan using governmental statistical data. BMJ open. 2020;10(8):e037537.
Ono Y, Sakai A, Otsuka K, . Effectiveness of a multimodal community intervention program to prevent suicide and suicide attempts: a quasi-experimental study. PLoS One. 2013;8(10):e74902.24130673
Oyama H, Sakashita T. Long-Term Effects of a Screening Intervention for Depression on Suicide Rates among Japanese Community-Dwelling Older Adults. Am J Geriatr Psychiatry. 2016;24(4):287–296.26796924
Oyama H, Sakashita T. Community-based screening intervention for depression affects suicide rates among middle-aged Japanese adults. Psychol Med. 2017;47(8):1500–1509.28193313
Page A, Taylor R, Gunnell D, Carter G, Morrell S, Martin G. Effectiveness of Australian youth suicide prevention initiatives. The British Journal of Psychiatry. 2011;199(5):423–9.22045948
Perceval M, Reddy P, Ross V, Joiner T, Kolves K. Evaluation of the SCARF Well-being and suicide prevention program for rural Australian communities. The Journal of Rural Health. 2020;36(2):247–54.31059168
Perron S, Burrows S, Fournier M, Perron PA, Ouellet F. Installation of a bridge barrier as a suicide prevention strategy in Montreal, Quebec, Canada. Am J Public Health. 2013;103(7):1235–1239.23678905
Pirruccello LM. Preventing adolescent suicide: a community takes action. J Psychosoc Nurs Ment Health Serv. 2010;48(5):34–41.
Rogers ML, Schneider ME, Gai AR, Gorday JY, Joiner TE. Evaluation of 2 web-based interventions in reducing the stigma of suicide. Behav Res Ther. 2018;109:49–55.30107279
Ross V, Koo YW, Kolves K. A suicide prevention initiative at a jumping site: A mixed-methods evaluation. EClinicalMedicine. 2020;19 (no pagination).
Saeheim A, Hestetun I, Mork E, Nrugham L, Mehlum L. A 12-year National Study of Suicide by Jumping From Bridges in Norway. Arch Suicide Res. 2017;21(4):568–576.27309998
Sareen J, Isaak C, Bolton SL, . Gatekeeper training for suicide prevention in First Nations community members: a randomized controlled trial. Depression and anxiety. 2013;30(10):1021–1029.23761133
Schilling EA, Aseltine RH, Jr., James A. The SOS Suicide Prevention Program: Further Evidence of Efficacy and Effectiveness. Prev Sci. 2016;17(2):157–166.26314868
Shelef L, Tatsa-Laur L, Derazne E, Mann JJ, Fruchter E. An effective suicide prevention program in the Israeli Defense Forces: A cohort study. Eur Psychiatry. 2016;31:37–43.26657599
Sinyor M, Levitt AJ. Effect of a barrier at Bloor Street Viaduct on suicide rates in Toronto: natural experiment. Bmj. 2010;341:c2884.20605890
Sinyor M, Schaffer A, Redelmeier DA, . Did the suicide barrier work after all? Revisiting the Bloor Viaduct natural experiment and its impact on suicide rates in Toronto. BMJ Open. 2017;7(5):e015299.
Smith-Osborne A, Maleku A, Morgan S. Impact of applied suicide intervention skills training on resilience and suicide risk in army reserve units. Traumatology. 2017;23(1):49–55.
Stack S. Crisis Phones - Suicide Prevention Versus Suggestion/Contagion Effects. Crisis. 2015;36(3):220–224.26122258
Szekely A, Konkoly Thege B, Mergl R, . How to decrease suicide rates in both genders? An effectiveness study of a community-based intervention (EAAD). PLoS One. 2013;8(9):e75081.24086443
Taylor-Rodgers E, Batterham PJ. Evaluation of an online psychoeducation intervention to promote mental health help seeking attitudes and intentions among young adults: randomised controlled trial. J Affect Disord. 2014;168:65–71.25038293
Till B, Sonneck G, Baldauf G, Steiner E, Niederkrotenthaler T. Reasons to love life. Effects of a suicide-awareness campaign on the utilization of a telephone emergency line in Austria. Crisis. 2013;34(6):382–389.23942384
Ueda M, Sawada Y, Matsubayashi T. The effectiveness of installing physical barriers for preventing railway suicides and accidents: evidence from Japan. J Affect Disord. 2015;178:1–4.25770476
Voss WD, Kaufman E, O’Connor SS, Comtois KA, Conner KR, Ries RK. Preventing addiction related suicide: a pilot study. J Subst Abuse Treat. 2013;44(5):565–569.23375569
Walrath C, Garraza LG, Reid H, Goldston DB, McKeon R. Impact of the Garrett Lee Smith youth suicide prevention program on suicide mortality. American Journal of Public Health. 2015;105(5):986–93.25790418
Wang J, Hausermann M, Berrut S, Weiss MG. The impact of a depression awareness campaign on mental health literacy and mental morbidity among gay men. J Affect Disord. 2013;150(2):306–312.23683994
Wasserman D, Hoven CW, Wasserman C, . School-based suicide prevention programmes: the SEYLE cluster-randomised, controlled trial. Lancet. 2015;385(9977):1536–1544.25579833
Yip PS, Law CK, Fu KW, Law YW, Wong PW, Xu Y. Restricting the means of suicide by charcoal burning. Br J Psychiatry. 2010;196(3):241–242.20194548