# APPENDIX 3 DEFINITIONS OF THE CDC STRATEGIES AND APPROACHES

Table 3-1 Definitions of the CDC Strategies and Approaches to Prevent Suicide Relevant for our Review^*, **^

Primary CDC Strategy | Approach | Definition from the CDC Technical Document
Strengthen economic supports | Household financial security | Strengthening household financial security can potentially buffer the risk of suicide by providing individuals with the financial means to lessen the stress and hardship associated with a job loss or other unanticipated financial problems. The provision of unemployment benefits and other forms of temporary assistance, livable wages, medical benefits, and retirement and disability insurance to help cover the cost of necessities or to offset costs in the event of disability, are examples of ways to strengthen household financial security.
Strengthen economic supports | Housing stabilization | Housing stabilization policies aim to keep people in their homes and provide housing options for those in need during times of financial insecurity. This may occur through programs that provide affordable housing such as through government subsidies or through other options available to potential homebuyers such as loan modification programs, move-out planning, or financial counseling services that help minimize the risk or impact of foreclosures and eviction.
Create protective environments | Reduce access to lethal means | Reduce access to lethal means among persons at risk of suicide. Means of suicide such as firearms, hanging/suffocation, or jumping from heights provide little opportunity for rescue and, as such, have high case fatality rates (eg, about 85% of people who use a firearm in a suicide attempt die from their injury). Research also indicates that: 1) the interval between deciding to act and attempting suicide can be as short as 5 or 10 minutes, and 2) people tend not to substitute a different method when a highly lethal method is unavailable or difficult to access. Therefore, increasing the time interval between deciding to act and the suicide attempt, for example, by making it more difficult to access lethal means, can be lifesaving. The following are examples of reducing access to lethal means: intervening at suicide hotspots and safe storage practices.
Create protective environments | Organizational policies and culture | Organizational policies and culture that promote protective environments may be implemented in places of employment, detention facilities, and other secured environments (eg, residential settings). Such policies and cultural values encourage leadership from the top down and may promote prosocial behavior (eg, asking for help), skill building, positive social norms, assessment, referral and access to helping services (eg, mental health, substance abuse treatment, financial counseling), and development of crisis response plans, postvention and other measures to foster a safe physical environment. Such policies and cultural shifts can positively impact organizational climate and morale and help prevent suicide and its related risk factors (eg, depression, social isolation).
Create protective environments | Community-based policies to reduce alcohol use | Community-based policies to reduce excessive alcohol use. Research studies in the United States have found that greater alcohol availability is positively associated with alcohol-involved suicides. Policies to reduce excessive alcohol use broadly include zoning to limit the location and density of alcohol outlets, taxes on alcohol, and bans on the sale of alcohol for individuals under the legal drinking age. These policies are important because acute alcohol use has been found to be associated with more than one-third of suicides and approximately 40% of suicide attempts.
Promote connectedness | Peer norm programs | Peer norm programs seek to normalize protective factors for suicide such as help-seeking, reaching out and talking to trusted adults, and promote peer connectedness. By leveraging the leadership qualities and social influence of peers, these approaches can be used to shift group-level beliefs and promote positive social and behavioral change. These approaches typically target youth and are delivered in school settings but can also be implemented in community settings.
Promote connectedness | Community engagement activities | Community engagement activities. Community engagement is an aspect of social capital. Community engagement approaches may involve residents participating in a range of activities, including religious activities, community clean-up and greening activities, and group physical exercise. These activities provide opportunities for residents to become more involved in the community and to connect with other community members, organizations, and resources, resulting in enhanced overall physical health, reduced stress, and decreased depressive symptoms, thereby reducing risk of suicide.
Teach coping and problem-solving skills | Social-emotional learning programs | Social-emotional learning programs focus on developing and strengthening communication and problem-solving skills, emotional regulation, conflict resolution, help seeking and coping skills. These approaches address a range of risk and protective factors for suicidal behavior. They provide children and youth with skills to resolve problems in relationships, school, and with peers, and help youth address other negative influences (eg, substance use) associated with suicide. These approaches are typically delivered to all students in a particular grade or school, although some programs also focus on groups of students considered to be at high risk for suicide. Opportunities to practice and reinforce skills are an important part of programs that work.
Teach coping and problem-solving skills | Parenting skills and family relationship approaches | Parenting skill and family relationship programs provide caregivers with support and are designed to strengthen parenting skills, enhance positive parent-child interactions, and improve children’s behavioral and emotional skills and abilities. Programs are typically designed for parents or caregivers with children in a specific age range and can be self-directed or delivered to individual families or groups of families. Some programs have sessions primarily with parents or caregivers while others include sessions for parents or caregivers, youth, and the family. Specific program content typically varies by the age of the child but often has consistent themes of child development, parent-child communication and relationships, and youth’s interpersonal and problem-solving skills.
Identify and support people at risk | Gatekeeper training | Gatekeeper training is designed to train teachers, coaches, clergy, emergency responders, primary and urgent care providers, and others in the community to identify people who may be at risk of suicide and to respond effectively, including facilitating treatment seeking and support services. Gatekeeper training may be implemented in a variety of settings to identify and support people at risk.
Identify and support people at risk | Crisis intervention | Crisis intervention. These approaches provide support and referral services, typically by connecting a person in crisis (or a friend or family member of someone at risk) to trained volunteers or professional staff via telephone hotline, online chat, text messaging, or in-person. Crisis intervention approaches are intended to impact key risk factors for suicide, including feelings of depression, hopelessness, and subsequent mental health care utilization. Similar to means reduction, crisis interventions can put space or time between an individual who may be considering suicide and harmful behavior.

CDC=Centers for Disease Control and Prevention

* Definitions are from the CDC document tilted “Preventing Suicide: A Technical Package of Policies, Programs, and Practices” published in 2017. Definitions were taken verbatim from the document except in select cases for brevity. Full citation listed in the reference list.

** For the purposes of our review, we modified the CDC framework by 1) adding a category for “public awareness and education campaigns” and a category for “screening for at-risk individuals (outside a health care setting)”; and 2) excluding the CDC strategies and approaches not relevant for our review.