# APPENDIX 2 RISK OF BIAS TOOL FOR OBSERVATIONAL STUDIES

Appendix Table 2-1 Modified JBI Critical Appraisal Checklist for Quasi-Experimental Studies

Question | Yes | No | Unclear | NA
Did the study include all eligible participants or were the participants a representative sample from the population of interest?; [underlined: Guidance to answer the question:]; Population-based studies: Were all eligible members of the population included?; Studies with a “sample” from the population: Is the representative sample similar to the population from which it is drawn?
Were the participants included in any comparison similar?; [underlined: Guidance to answer the question:]; If baseline demographic data are provided, are there statistically significant differences between the groups (eg age, gender, risk factors)?; In 1 group, pre-test/post-test studies where the participants are the same in any pre-post comparisons, the answer to this question should be ‘yes’.; NOTE: Selection bias is defined “as a nonrandom imbalance among treatment groups of the distribution of factors capable of influencing the end points.” This definition is from the Handbook of Pharmacogenomics and Stratified Medicine 2014.
Were the participants included in any comparisons receiving similar treatment/care, other than the exposure or intervention of interest?; [underlined: Guidance to answer the question:]; Did 1 group get any additional suicide prevention information/intervention? For example, if a study is exploring the effect of means restriction, did the intervention group also receive any other exposure (eg awareness campaign)?; It is acceptable for all participants to be receiving some type of intervention provided the “intervention” group is receiving an additional intervention. The intervention of interest is the additional intervention.
Was the control group concurrent?; [underlined: Guidance to answer the question:]; Sampled and followed over the same period of time?
For pre-post studies, were there multiple measurements of the outcome both pre and post the intervention/exposure?; [underlined: Guidance to answer the question:]; Example: the study was between 2010 and 2017 and the intervention was initiated in 2014. Were there multiple measurements prior to 2014 and then after the intervention (2010, 2011, etc. and then 2016, 2017, etc.)
Was follow-up complete?; [underlined: Guidance to answer the question:]; For pre-post studies that are population-based: answer “not applicable”.; For studies that have a separate comparison group and a defined cohort: was there complete information on a high percentage of participants? Make a judgement on a case-by-case basis (no set threshold).
Were completeness of follow-up similar for study groups?; [underlined: Guidance to answer the question:]; For pre-post studies that are population-based: answer “not applicable”.; For studies that have a separate comparison group and a defined cohort: Were there differences between groups with regards to loss to follow up (large loss in 1 group versus the other) or differences in length of follow-up (one group followed to study end, 1 not)?
Were the outcomes of participants included in any comparisons measured in the same way?; [underlined: Guidance to answer the question:]; Same method (questionnaires, registries, death certificates, ICD-10 codes) used for both groups?
Were suicide deaths and/or attempts measured in a reliable way?; [underlined: Guidance to answer the question:]; Were data collected in a way that could be repeated (eg, death registry vs reported in interview with neighbors)?
Were other eligible outcomes measured in a reliable way?; [underlined: Guidance to answer the question:]; Were other outcomes assessed in the study groups (or pre/post) with the same instruments and by similar methods of assessment?
Did the study adjust for confounding variables?; [underlined: Guidance to answer the question:]; Did the statistical methods adjust for baseline variables considered to be confounders (examples may include age, gender, race, SES, history of suicide attempt, mental health diagnoses)? If the study attempted to adjust for any confounders, then answer “yes”.

NA=not applicable