# APPENDIX 1 SEARCH STRATEGIES

Database: MEDLINE

1 | exp Suicide, Completed/ | 41
2 | exp *Suicide, Attempted/pc [Prevention & Control] | 938
3 | ((suicid* or self harm* or self injur* or self hatred or self directed violence) adj2 (prevent* or control* or reduc* or manag*)).ti,ab. | 9021
4 | 1 or 2 or 3 | 9657
5 | (intervention* or program* or strateg* or polic* or resource* or promotion* or campaign* or modul* or activit* or project* or training or implement* or limit* or restrict* or initiative* or barrier* or helpline or hotspot*).ti,ab. | 8257659
6 | 4 and 5 | 5729
7 | limit 6 to (english language and humans and yr=“2010 -Current”) | 2701
8 | (child* or youth* or preteen* or pediatric* or paediatric*).ti,ab. | 1560906
9 | ((elementary or primary or grammar or grade) adj1 school).ti,ab. | 16877
10 | 8 or 9 | 1565248
11 | 7 not 10 | 2255
12 | (hospital* or inpatient* or medic* ward* or emergency department*).ti,ab. | 1346476
13 | 11 not 12 | 1826
14 | limit 13 to (meta analysis or “systematic review”) | 111
15 | limit 13 to (address or biography or case reports or comment or congress or consensus development conference or editorial or interactive tutorial or interview or legal case or legislation or letter or news or newspaper article or observational study, veterinary or personal narrative or portrait or video-audio media or webcast) | 83
16 | 13 not 15 | 1743

Database: Embase

1 | exp *suicide/pc [Prevention] | 4725
2 | exp *Suicide, Attempted/pc [Prevention & Control] | 876
3 | ((suicid* or self harm* or self injur* or self hatred or self directed violence) adj2 (prevent* or control* or reduc* or manag*)).ti,ab. | 10850
4 | 1 or 2 or 3 | 13816
5 | (intervention* or program* or strateg* or polic* or resource* or promotion* or campaign* or modul* or activit* or project* or training or implement* or limit* or restrict* or initiative* or barrier* or helpline or hotspot*).ti,ab. | 10747946
6 | 4 and 5 | 7279
7 | limit 6 to (english language and humans and yr=“2010 -Current”) | 4381
8 | (child* or youth* or preteen or pediatric* or paediatric*).ti,ab. | 2173177
9 | ((elementary or primary or grammar or grade) adj1 school).ti,ab. | 22099
10 | 8 or 9 | 2179108
11 | 7 not 10 | 3556
12 | (hospital* or inpatient* or medic* ward* or emergency department*).ti,ab. | 2125475
13 | 11 not 12 | 2848
14 | limit 13 to (books or chapter or conference abstract or conference paper or “conference review” or letter or note) | 478
15 | 13 not 14 | 2370
16 | limit 15 to (book or book series or conference proceeding) | 7
17 | 15 not 16 | 2363
18 | (case adj2 (report or descri*)).ti,ab. | 636751
19 | (“reviews the book” or “comments on an article”).ab. | 103
20 | 18 or 19 | 636853
21 | 17 not 20 | 2354

Database: PsycINFO

1 | *Suicide/ or *Attempted Suicide/ | 29386
2 | (prevent* or control or reduc* or manag*).ti,ab. | 1148355
3 | 1 and 2 | 10603
4 | *Suicide Prevention/ or *Suicide Prevention Centers/ | 3919
5 | ((suicid* or self harm* or self injur* or self hatred or self directed violence) adj2 (prevent* or control* or reduc* or manag*)).ti,ab. | 9335
6 | 3 or 4 or 5 | 15388
7 | (intervention* or program* or strateg* or polic* or resource* or promotion* or campaign* or modul* or postvention* or activit* or project* or training or implement* or limit* or restrict* or initiative* or barrier* or helpline or hotspot*).ti,ab. | 1988975
8 | 6 and 7 | 9156
9 | (child* or youth* or preteen or pediatric* or paediatric*).ti,ab. | 752753
10 | ((elementary or primary or grammar or grade) adj1 school).ti,ab. | 33533
11 | 9 or 10 | 766815
12 | 8 not 11 | 7504
13 | (hospital* or inpatient* or medic* ward* or emergency department*).ti,ab. | 185108
14 | 12 not 13 | 6359
15 | limit 14 to (human and english language and yr=“2010-Current”) | 3285
16 | (case adj2 (report or descri*)).ti,ab. | 30537
17 | 15 not 16 | 3266
18 | limit 17 to “0110 peer-reviewed journal” | 2644
19 | limit 18 to (chapter or “column/opinion” or dissertation or editorial or encyclopedia entry or interview or letter or obituary or poetry or publication information or reprint or review-book or review-media or review-software & other) | 183
20 | 18 not 19 | 2461

Database: Sociological Abstracts

mainsubject.Exact(“suicide, attempted” OR “suicide”) AND ab(prevent* OR control OR reduc* OR manag*) OR ab(suicid* OR self harm* OR self injur* OR self hatred OR self directed violence) AND ab(prevent* OR control OR reduc* OR manag*) AND ab(intervention* OR program* OR strateg* OR polic* OR resource* OR promotion* OR campaign* OR modul* OR activit* OR project* OR training OR implement* OR limit* OR restrict* OR initiative* OR barrier* OR helpline OR hotspot*) NOT ab((child* OR youth* OR preteen OR pediatric* OR paediatric* OR ((elementary OR primary OR grammar OR grade) NEAR/1 school))) NOT ab(hospital* OR inpatient* OR medic* ward* OR emergency department)

Databases: Sociological Abstracts

Limited by:

Peer reviewed,

Date: From January 01 2010 to May 31 2020

Source type:

Scholarly Journals

Document type:

Article, Literature Review

Language:

English

Narrowed by:

Peer reviewed: Peer reviewed