# References

1 Federal Register. Grants for Adaptive Sports Programs for Disabled Veterans and Disabled Members of the Armed Forces. 2014. https://www.federalregister.gov/documents/2014/07/01/2014-15191/grants-for-adaptive-sports-programs-for-disabled-veterans-and-disabled-members-of-the-armed-forces. Accessed 19 April 2018.
2 Disabled Sports USA - Early History. https://www.disabledsportsusa.org/about/our-mission/early-history/. Accessed 7 December 2018.
3 Adnan Y, McKenzie A, Miyahara M. Self-efficacy for quad rugby skills and activities of daily living. Adapt Phys Activ Q. 2001;18(1):90–101.
4 Akbar M, Brunner M, Ewerbeck V, . Do overhead sports increase risk for rotator cuff tears in wheelchair users? Arch Phys Med Rehabil. 2015;96(3):484–488.25449196
5 Arnold R, Wagstaff CR, Steadman L, Pratt Y. The organisational stressors encountered by athletes with a disability. J Sports Sci. 2017;35(12):1187–1196.27472292
6 Ashton-Shaeffer C, Gibson H, Holt M, Williming C. Women’s resistance and empowerment through wheelchair sport. World Leis J. 2001;43(4):11–21.
7 Aydoğ E, Aydog ST, Cakci A, Doral MN. Dynamic postural stability in blind athletes using the Biodex Stability System. Int J Sports Med. 2006;27(5):415–418.16729385
8 Aytar A, Pekyavas NO, Ergun N, Karatas M. Is there a relationship between core stability, balance and strength in amputee soccer players? A pilot study. Prosthet Orthot Int. 2012;36(3):332–338.22918911
9 Barbin JM, Ninot G. Outcomes of a skiing program on level and stability of self-esteem and physical self in adults with spinal cord injury. Int J Rehabil Res. 2008;31(1):59–64.18277205
10 Bauerfeind J, Koper M, Wieczorek J, Urbanski P, Tasiemski T. Sports injuries in wheelchair rugby - a pilot study. J Hum Kinet. 2015;48:123–132.26834880
11 Beinotti F, Christofoletti G, Correia N, Borges G. Effects of horseback riding therapy on quality of life in patients post stroke. Top Stroke Rehabil. 2013;20(3):226–232.23841970
12 Beinotti F, Correia N, Christofoletti G, Borges G. Use of hippotherapy in gait training for hemiparetic post-stroke. Arq Neuropsiquiatr. 2010;68(6):908–913.21243251
13 Bennett JL, Lundberg NR, Zabriskie R, Eggett D. Addressing posttraumatic stress among Iraq and Afghanistan Veterans and significant others: an intervention utilizing sport and recreation. Ther Recreation J. 2014;48(1):74–93.
14 Bennett JL, Piatt JA, Van Puymbroeck M. Outcomes of a therapeutic fly-fishing program for Veterans with combat-related disabilities: a community-based rehabilitation initiative. Community Ment Health J. 2017;53(7):756–765.28303444
15 Bennett JL, Van Puymbroeck M, Piatt JA, Rydell RJ. Veterans’ perceptions of benefits and important program components of a therapeutic fly-fishing program. Ther Recreation J. 2014;48(2):169–187.
16 Blauwet C, Sudhakar S, Doherty AL, Garshick E, Zafonte R, Morse LR. Participation in organized sports is positively associated with employment in adults with spinal cord injury. Am J Phys Med Rehabil. 2013;92(5):393–401.23478458
17 Blauwet CA, Cushman D, Emery C, . Risk of injuries in Paralympic track and field differs by impairment and event discipline: a prospective cohort study at the London 2012 Paralympic Games. Am J Sports Med. 2016;44(6):1455–1462.26920432
18 Blauwet CA, Yang HY, Cruz SA, . Functional and environmental factors are associated with sustained participation in adaptive sports. PM R. 2017;9(7):668–675.27810582
19 Boninger ML, Robertson RN, Wolff M, Cooper RA. Upper limb nerve entrapments in elite wheelchair racers. Am J Phys Med Rehabil. 1996;75(3):170–176.8663922
20 Bragança S, Castellucci I, Gill S, Matthias P, Carvalho M, Arezes P. Insights on the apparel needs and limitations for athletes with disabilities: The design of wheelchair rugby sports-wear. Appl Ergon. 2018;67:9–25.29122204
21 Bragaru M, Dekker R, Dijkstra PU, Geertzen JH, van der Sluis CK. Sports participation of individuals with major upper limb deficiency. Br J Sports Med. 2015;49(5):330–334.23956335
22 Bragaru M, Meulenbelt HEJ, Dijkstra PU, Geertzen JHB, Dekker R. Sports participation of Dutch lower limb amputees. Prosthet Orthot Int. 2013;37(6):454–458.23436692
23 Bragaru M, van Wilgen CP, Geertzen JH, Ruijs SG, Dijkstra PU, Dekker R. Barriers and facilitators of participation in sports: a qualitative study on Dutch individuals with lower limb amputation. PLoS One. 2013;8(3):e59881.23533655
24 Broman D, Ahmed OH, Tscholl PM, Weiler R. Medication and supplement use in disability football world championships. PM R. 2017;9(10):990–997.28363689
25 Calsius J, Courtois I, Feys P, Van Asch P, De Bie J, D’hooghe M. “How to conquer a mountain with multiple sclerosis”. How a climbing expedition to Machu Picchu affects the way people with multiple sclerosis experience their body and identity: a phenomenological analysis. Disabil Rehabil. 2015;37(26):2393–2399.25786475
26 Campayo-Piernas M, Caballero C, Barbado D, Reina R. Role of vision in sighted and blind soccer players in adapting to an unstable balance task. Exp Brain Res. 2017;235(4):1269–1279.28197674
27 Campbell E, Jones G. Sources of stress experienced by elite male wheelchair basketball players. Adapt Phys Activ Q. 2002;19(1):82.28195795
28 Campbell E, Jones G. Cognitive appraisal of sources of stress experienced by elite male wheelchair basketball players. Adapt Phys Activ Q. 2002;19(1):100.28195796
29 Carin-Levy G, Jones D. Psychosocial aspects of scuba diving for people with physical disabilities: An occupational science perspective. Can J Occup Ther. 2007;74(1):6–14.17319318
30 Carless D. Narrative transformation among military personnel on an adventurous training and sport course. Qual Health Res. 2014;24(10):1440–1450.25147220
31 Carless D, Peacock S, McKenna J, Cooke C. Psychosocial outcomes of an inclusive adapted sport and adventurous training course for military personnel. Disabil Rehabil. 2013;35(24):2081–2088.23781910
32 Chard S. Qualitative perspectives on aquatic exercise initiation and satisfaction among persons with multiple sclerosis. Disabil Rehabil. 2017;39(13):1307–1312.27346481
33 Côté-Leclerc F, Boileau Duchesne G, Bolduc P, . How does playing adapted sports affect quality of life of people with mobility limitations? Results from a mixed-method sequential explanatory study. Health Qual Life Outcomes. 2017;15 (1) (no pagination)(22).
34 Curtis KA, Black K. Shoulder pain in female wheelchair basketball players. J Orthop Sports Phys Ther. 1999;29(4):225–231.10322595
35 da Silva ES, Fischer G, da Rosa RG, . Gait and functionality of individuals with visual impairment who participate in sports. Gait Posture. 2018;62:355–358.29614469
36 Derman W, Runciman P, Schwellnus M, . High precompetition injury rate dominates the injury profile at the Rio 2016 Summer Paralympic Games: a prospective cohort study of 51198 athlete days. Br J Sports Med. 2018;52(1):24–31.29030389
37 D’hooghe MB FP, Deltour S, .. Impact of a 5-day expedition to Machu Picchu on persons with multiple sclerosis. Multiple Scl Int. 2014;2014(761210).
38 Earles JL, Vernon LL, Yetz JP. Equine-assisted therapy for anxiety and posttraumatic stress symptoms. J Trauma Stress. 2015;28(2):149–152.25782709
39 Eilat R, Hazor B, Carmeli E. Association between quality of life and team achievement among wheelchair basketball players - A survey study. Int J Disabil Hum Dev. 2015;14(2):161–166.
40 Fagher K, Jacobsson J, Dahlstrom O, Timpka T, Lexell J. An eHealth application of self-reported sports-related injuries and illnesses in Paralympic sport: pilot feasibility and usability study. JMIR Hum Factors. 2017;4(4):e30.29187343
41 Ferrara MS, Buckley WE. Athletes with disabilities injury registry. Adapt Phys Activ Q. 1996;13(1):50–60.
42 Fiorilli G, Iuliano E, Aquino G, . Mental health and social participation skills of wheelchair basketball players: a controlled study. Res Dev Disabil. 2013;34(11):3679–3685.24012595
43 Foreman PE, Cull J, Kirkby RJ. Sports participation in individuals with spinal cord injury: Demographic and psychological correlates. Int J Rehabil Res. 1997;20(2):159–168.9226499
44 Fullerton HD, Borckardt JJ, Alfano AP. Shoulder pain: a comparison of wheelchair athletes and nonathletic wheelchair users. Med Sci Sports Exerc. 2003;35(12):1958–1961.14652488
45 Garshick E, Mulroy S, Graves DE, Greenwald K, Horton JA, Morse LR. Active lifestyle Is associated with reduced dyspnea and greater life satisfaction in spinal cord injury. Arch Phys Med Rehabil. 2016;97(10):1721–1727.26951870
46 Giacobbi PR, Jr., Stancil M, Hardin B, Bryant L. Physical activity and quality of life experienced by highly active individuals with physical disabilities. Adapt Phys Activ Q. 2008;25(3):189–207.18765861
47 Goodwin D, Johnston K, Gustafson P, Elliott M, Thurmeier R, Kuttai H. It’s okay to be a quad: wheelchair rugby players’ sense of community. Adapt Phys Activ Q. 2009;26(2):102–117.19478344
48 Guchan Z, Bayramlar K, Ergun N. Determination of the effects of playing soccer on physical fitness in individuals with transtibial amputation. J Sports Med Phys Fitness. 2017;57(6):879–886.27054354
49 Hammer A, Nilsagard Y, Forsberg A, Pepa H, Skargren E, Oberg B. Evaluation of therapeutic riding (Sweden)/hippotherapy (United States). A single-subject experimental design study replicated in eleven patients with multiple sclerosis. Physiother Theory Pract. 2005;21(1):51–77.16385943
50 Hanson CS, Nabavi D, Yuen HK. The effect of sports on level of community integration as reported by persons with spinal cord injury. Am J Occup Ther. 2001;55(3):332–338.11723975
51 Hawkeswood J, Finlayson H, O’Connor R, Anton H. A pilot survey on injury and safety concerns in international sledge hockey. Int J Sports Phys Ther. 2011;6(3):173–185.21904696
52 Hawkins BL, Cory AL, Crowe BM. Effects of participation in a Paralympic military sports camp on injured service members: implications for theraputic recreation. Ther Recreation J. 2011;45(4):309–325.
53 Haykowsky MJ, Warburton DER, Art Quinney H. Pain and injury associated with powerlifting training in visually impaired athletes. J Vis Impair Blind.. 1999;93(4):236–241.
54 Herzog T, Swanenburg J, Hupp M, Mittaz Hager AG. Effect of indoor wheelchair curling training on trunk control of person with chronic spinal cord injury: a randomised controlled trial. Spinal Cord Ser Cases. 2018;4:26.
55 Jaarsma EA, Dekker R, Koopmans SA, Dijkstra PU, B. Geertzen JH. Barriers to and facilitators of sports participation in people with visual impairments. Adapt Phys Activ Q. 2014;31(3):240–264.25028476
56 Jaarsma EA, Geertzen JH, de Jong R, Dijkstra PU, Dekker R. Barriers and facilitators of sports in Dutch Paralympic athletes: An explorative study. Scand J Med Sci Sports. 2014;24(5):830–836.23662691
57 Jackson DL, Hynninen BC, Caborn DN, McLean J. Electrodiagnostic study of carpal tunnel syndrome in wheelchair basketball players. Clin J Sport Med. 1996;6(1):27–31.8925362
58 Johnson RA, Albright DL, Marzolf JR, . Effects of therapeutic horseback riding on post-traumatic stress disorder in military veterans. Mil Med Res. 2018;5 (1) (no pagination)(3).
59 Jolk C, Dalgas U, Osada N, Platen P, Marziniak M. Effects of sports climbing on muscle performance and balance for patients with multiple sclerosis: A case series. Int J Ther Rehabil. 2015;22(8):371–376.
60 Kars C, Hofman M, Geertzen JH, Pepping GJ, Dekker R. Participation in sports by lower limb amputees in the Province of Drenthe, The Netherlands. Prosthet Orthot Int. 2009;33(4):356–367.19947822
61 Kim W, Lee L, Lans D, Tostenrude D, Lee K. Perception of employment by the Veterans participating in the National Veterans Wheelchair Games: a survey study. PM R. 2018;10(3):263–268.28939461
62 Kurková P, Valkova H, Scheetz N. Factors impacting participation of European elite deaf athletes in sport. J Sports Sci. 2011;29(6):607–618.21360404
63 Laferrier JZ, Teodorski E, Cooper RA. Investigation of the impact of sports, exercise, and recreation participation on psychosocial outcomes in a population of Veterans with disabilities: A Cross-sectional Study. Am J Phys Med Rehabil. 2015;94(12):1026–1034.25768065
64 Lanning BA, Krenek N. Examining effects of equine-assisted activities to help combat veterans improve quality of life. J Rehabil Res Dev. 2013;50(8):vii–xiii.
65 Lape EC, Katz JN, Losina E, Kerman HM, Gedman MA, Blauwet CA. Participant-reported benefits of involvement in an adaptive sports program: a qualitativestudy. PM R. 2018;10(5):507–515.29111464
66 Lastuka A, Cottingham M. The effect of adaptive sports on employment among people with disabilities. Disabil Rehabil. 2015:1–7.
67 Lindroth JL, Sullivan JL, Silkwood-Sherer D. Does hippotherapy effect use of sensory information for balance in people with multiple sclerosis? Physiother Theory Pract. 2015;31(8):575–581.26467902
68 Litchke LG, Hodges JS, Schmidt EA, Lloyd LK, Payne E, Russian CJ. Personal meaning of wheelchair rugby participation by five male athletes. Ther Recreation J. 2012;46(1):26–41.
69 Littman AJ, Bouldin ED, Haselkorn JK. This is your new normal: A qualitative study of barriers and facilitators to physical activity in Veterans with lower extremity loss. Disabil Health J. 2017;10(4):600–606.28377115
70 Lundberg N, Bennett J, Smith S. Outcomes of adaptive sports and recreation participation among Veterans returning from combat with acquired disability. Ther Recreation J. 2011;45(2):105–120.
71 Macdougall H, O’Halloran P, Sherry E, Shields N. Needs and strengths of Australian para-athletes: identifying rheir subjective psychological, social, and physical health and well-being. Sport Psychol. 2016;30(1):1–12.
72 Magno e Silva M, Bilzon J, Duarte E, Gorla J, Vital R. Sport injuries in elite paralympic swimmers with visual impairment. J Athl Train. 2013;48(4):493–498.23768122
73 Magno e Silva M, Morato, Bilzon JLJ, Duarte E. Sports injuries in Brazilian blind footballers. Int J Sports Med. 2013;34(3):239–243.22972238
74 Magno e Silva M, Winckler C, Costa e Silva A, Bilzon J, Duarte E. Sports injuries in Paralympic track and field athletes with visual impairment. Med Sci Sports Exerc. 2013;45(5):908–913.23247703
75 Malinowski K, Yee C, Tevlin JM, . The effects of equine-assisted activities therapy on plasma cortisol and oxytocin concentrations and heart rate variability in horses and measures of symptoms of posttraumatic stress disorder in Veterans. J Equine Vet Sci. 2018;64:17–26.30973147
76 McVeigh SA, Hitzig SL, Craven BC. Influence of sport participation on community integration and quality of life: A comparison between sport participants and non-sport participants with spinal cord injury. J Spinal Cord Med. 2009;32(2):115–124.19569458
77 Miki Y, Kanayama C, Nakashima S, Yamasaki M. Health-related quality of life in active persons with spinal cord injury. Jpn Phys Fit Sports Med. 2012;61(2):177–182.
78 Molik B, Zubala T, Słyk K, Bigas G, Gryglewicz A, Kucharczyk B. Motivation of the disabled to participate in chosen Paralympics events (wheelchair basketball, wheelchair rugby, and boccia). Physiotherapy / Fizjoterapia. 2010;18(1):42–51.
79 Mowatt RA, Bennett J. War narratives: Veteran stories, PTSD effects, and therapeutic fly-fishing. Ther Recreation J. 2011;45(4):286–308.
80 Munoz-Lasa S, Ferriero G, Valero R, Gomez-Muniz F, Rabini A, Varela E. Effect of therapeutic horseback riding on balance and gait of people with multiple sclerosis. G Ital Med Lav Ergon. 2011;33(4):462–467.22452106
81 Muraki S, Tsunawake N, Hiramatsu S, Yamasaki M. The effect of frequency and mode of sports activity on the psychological status in tetraplegics and paraplegics. Spinal Cord. 2000;38(5):309–314.10822404
82 Nam JS, Lee KE, Jun AY, Parke CS, Kim HY, Chae YH. Dilemmas of Korean athletes with a spinal cord injury to participate in sports: a survey based on the ICF Core Set for Spinal Cord Injury. Ann Phys Rehabil Med. 2016;40(5):893–901.
83 Nettleton L, Hassett L, Scheibe F, Price R, Kirkham C, Sherrington C. Sport and physical activity participation among people with disabilities reported at a sports exhibition and six months later. Ther Recreation J. 2017;51(3):206–220.
84 Olenik LM, Matthews JM, Steadward RD. Women, disability and sport: unheard voices. Can Womens Stud. 1995;15(4):54–57.
85 O’Neill SB, Maguire S. Patient perception of the impact of sporting activity on rehabilitation in a spinal cord injuries unit. Spinal Cord. 2004;42(11):627–630.15289808
86 Perrier MJ, Latimer-Cheung AE, Ginis KAM. An investigation of seasonal variation in leisure-time physical activity in persons with spinal cord injury. Spinal Cord. 2012;50(7):507–511.22391685
87 Perrier MJ, Shirazipour CH, Latimer-Cheung AE. Sport participation among individuals with acquired physical disabilities: group differences on demographic, disability, and Health Action Process Approach constructs. Disabil Health J. 2015;8(2):216–222.25458978
88 Phillips AA, Squair JR, Currie KD, Tzeng YC, Ainslie PN, Krassioukov AV. 2015 ParaPan American Games: autonomic function, but not physical activity, is associated with vascular-cognitive impairment in spinal cord injury. J Neurotrauma. 2017;34(6):1283–1288.27998205
89 Pluym SM, Keur TJ, Gerritsen J, Post MW. Community integration of wheelchair-bound athletes: a comparison before and after onset of disability. Clin Rehabil. 1997;11(3):227–235.9360035
90 Ponchillia PE, Strause B, Ponchillia SV. Athletes with visual impairments: Attributes and sports participation. Journal of Visual Impairment and Blindness. 2002;96(4):267–272.
91 Prokopowicz G, Molik B, Prokopowicz K, . Motives for participation in Paralympic sailing - opinions of Polish and foreign athletes with physical disabilities. Postepy Rehabilitacji. 2016;30(3):17–26.
92 Rauch A, Fekete C, Oberhauser C, Marti A, Cieza A. Participation in sport in persons with spinal cord injury in Switzerland. Spinal Cord. 2014;52(9):706–711.24937697
93 Rogers CM, Mallinson T, Peppers D. High-intensity sports for posttraumatic stress disorder and depression: feasibility study of ocean therapy with veterans of Operation Enduring Freedom and Operation Iraqi Freedom. Am J Occup Ther. 2014;68(4):395–404.25005502
94 Sá MM, Azevedo R, Martins MC, Machado O, Tavares J. Accessibility of sports facilities for persons with reduced mobility and assessment of their motivation for practice. Work. 2012;41 Suppl 1:2017–2023.22317013
95 Scarpa S. Physical self-concept and self-esteem in adolescents and young adults with and without physical disability: the role of sports participation. Eur J Adap Phys Act. 2011;4(1):38–53.
96 Schachten T, Jansen P. The effects of golf training in patients with stroke: A pilot study. Int Psychogeriatr. 2015;27(5):865–873.25567412
97 Shatil S, Ivanova TD, Mochizuki G, Garland SJ. Effects of therapeutic golf rehabilitation on golf performance, balance, and quality of life in individuals following stroke: pilot study. Physiother Canada. 2005;57(2):101–112.
98 Shimizu Y, Mutsuzaki H, Tachibana K, . A survey of deep tissue injury in elite female wheelchair basketball players. J Back Musculoskelet Rehabil. 2017;30(3):427–434.27858684
99 Silkwood-Sherer D, Warmbier H. Effects of hippotherapy on postural stability, in persons with multiple sclerosis: a pilot study. J Neurol Phys Ther. 2007;31(2):77–84.17558361
100 Silveira SL, Ledoux T, Cottingham M, Hernandez DC. Association among practice frequency on depression and stress among competitive US male wheelchair rugby athletes with tetraplegia. Spinal Cord. 2017;55(10):957–962.28508888
101 Skordilis EK, Koutsouki D, Asonitou K, Evans E, Jensen B, Wall K. Sport orientations and goal perspectives of wheelchair athletes. Adapt Phys Activ Q. 2001;18(3):304–315.
102 Skučas K. Obstacles and possibilities for participation in sport after spinal cord injury. Educ Physical Train Sport. 2013;88(1):82–87.
103 Sporner ML, Fitzgerald SG, Dicianno BE, . Psychosocial impact of participation in the National Veterans Wheelchair Games and Winter Sports Clinic. Disabil Rehabil. 2009;31(5):410–418.18608391
104 Stephens C, Neil R, Smith P. The perceived benefits and barriers of sport in spinal cord injured individuals: a qualitative study. Disabil Rehabil. 2012;34(24):2061–2070.22494335
105 Tasiemski T, Brewer BW. Athletic identity, sport participation, and psychological adjustment in people with spinal cord injury. Adapt Phys Activ Q. 2011;28(3):233–250.21725116
106 Tasiemski T, Kennedy P, Gardner BP, Blaikley RA. Athletic identity and sports participation in people with spinal cord injury. Adapt Phys Activ Q. 2004;21(4):364–378.
107 Tasiemski T, Kennedy P, Gardner BP, Taylor N. The association of sports and physical recreation with life satisfaction in a community sample of people with spinal cord injuries. NeuroRehabilitation. 2005;20(4):253–265.16403994
108 Tasiemski T, Wilski M, Mȩdak K. An assessment of athletic identify in blind and able-bodies tandem cyclists. Hum Mov. 2012;13(2):178–184.
109 Taylor LP, McGruder JE. The meaning of sea kayaking for persons with spinal cord injuries. Am J Occup Ther. 1996;50(1):39–46.8644835
110 Urbański P, Bauerfeind J, PokaczajŁO J. Community integration in persons with spinal cord injury participating in team and individual sports. Trends Sport Sci.. 2013;20(2):95–100.
111 Ustunkaya O, Edeer AO, Donat H, Yozbatiran N. Shoulder pain, functional capacity and quality of life in professional wheelchair basketball players and non-athlete wheelchair users. Pain Clinic. 2007;19(2):71–76.
112 Velikonja O, Curic K, Ozura A, Jazbec SS. Influence of sports climbing and yoga on spasticity, cognitive function, mood and fatigue in patients with multiple sclerosis. Clin Neurol Neurosurg. 2010;112(7):597–601.20371148
113 Vella EJ, Milligan B, Bennett JL. Participation in outdoor recreation program predicts improved psychosocial well-being among veterans with post-traumatic stress disorder: a pilot study. Mil Med. 2013;178(3):254–260.23707110
114 Vermöhlen V, Schiller P, Schickendantz S, . Hippotherapy for patients with multiple sclerosis: A multicenter randomized controlled trial (MS-HIPPO). Mult Scler J. 2017;01.
115 Wickham SE, Hanson CS, Shechtman O, Ashton C. A pilot study: attitudes toward leisure and leisure motivation in adults with spinal cord injury. Occup Ther Health Care. 2000;12(4):33–50.
116 Wu SK, Williams T. Factors influencing sport participation among athletes with spinal cord injury. Med Sci Sports Exerc. 2001;33(2):177–182.11224802
117 Yazicioglu K, Yavuz F, Goktepe AS, Tan AK. Influence of adapted sports on quality of life and life satisfaction in sport participants and non-sport participants with physical disabilities. Disabil Health J. 2012;5(4):249–253.23021735
118 You BC, Lee WJ, Lee SH, Jang S, Lee HS. Shoulder disease patterns of the wheelchair athletes of table-tennis and archery: a pilot study. Ann Phys Rehabil Med. 2016;40(4):702–709.
119 Zoerink DA, Carter MJ. A case report of a physical activity intervention for adults with stroke. Ther Recreation J. 2015;49(3):238–252.
120 Zwierzchowska A, Zebrowska A, Szkwara M. Sports activities and satisfaction of living of men after cervical spinal cord injury. Pol Ann Med. 2017;24(2):205–208.
121 Mulligan HF, Hale LA, Whitehead L, Baxter GD. Barriers to physical activity for people with long-term neurological conditions: a review study. Adapt Phys Activ Q. 2012;29:243–265.22811565
122 World Health Organization. International Classification of Functioning, Disability and Health (ICF). https://www.who.int/classifications/icf/en/. Accessed 22 February 2019.
123 van der Ploeg HP, van der Beek AJ, van der Woude LHV, van Mechelen W. Physical activity for people with a disability: a conceptual model. Sports Med. 2004;34(10):639–649.15335241
124 Gailey RS, Cooper RA. Sports - medicine for the disabled. The time for specialization in prosthetics and orthotics is now. Prosthet Orthot Int. 2009;33(3):187–191.19658008