# Acknowledgments

This topic was developed in response to a nomination by Lucille Beck, PhD and Joel Scholten, MD for the purpose of determining the benefits and harms associations with participation in adaptive sports for Veterans with disabilities as well as to identify facilitators and barriers to participation. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Lucille Beck, PhD
  Deputy Chief Patient Care Services Officer, Rehabilitation & Prosthetic Services
- Joel Scholten, MD
  National Director, VHA Physical Medicine and Rehabilitation Services
- Leif Nelson, DPT, ATP, CSCS
  Director, National Veterans Sports Programs & Special Events
- David Chandler, PhD
  Deputy Chief Consultant, Rehabilitation and Prosthetic Services

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Rory Cooper, PhD
  Director, Human Engineering Research Laboratories
  Pittsburgh VAMC/University of Pittsburgh
  Pittsburgh, PA
- M. Jason Highsmith, PhD, PT, DPT, CP, FAAOP
  National Director, Orthotic and Prosthetic Clinical Services
  Rehabilitation and Prosthetics Service
  Washington, DC
- Kenneth Lee, MD
  Chief of Spinal Cord Injury Division
  Clement J. Zablocki VA Medical Center
  Milwaukee WI
- Jennifer Piatt, PhD, CTRS
  Graduate Coordinator and Associate Professor, School of Public Health
  Indiana University
  Bloomington, IN
- Italia M. Wickremasinghe, MD
  Executive Director, Spinal Cord Injuries and Disorders (SCI/D) System of Care
  SCI/D National Program Office
  VA North Texas Health Care System
  Dallas, TX

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.