# Summary and Discussion

## Summary of Evidence

### Key Questions 1-3

Evidence for the effectiveness of adaptive sports programs is limited in quantity, quality, and applicability. Findings come largely from observational studies of EAAT in selected populations with PTSD (including US Veterans), MS, or CVA who agreed to participate in these programs. Many outcomes of interest were infrequently reported, including self-esteem/perceived competence, community integration/social functioning, and employment. No studies reported on health care utilization.

Evidence for the effectiveness of adaptive sports activity participation is largely from observational studies enrolling selected individuals with SCI and involving multiple sports. We found no studies exclusively enrolling individuals with PTSD, CVA, TBI, MS, ALS, or hearing loss or deafness, and few studies limited to a specific adaptive sport.

There was little evidence of harms associated with adaptive sports program participation, although few adaptive sport or populations of interest were represented in the literature. Few studies were designed to capture specific harms associated with participation.

Barriers to participation were similar across sports and population and were mainly due to physical environmental factors including lack of information, cost, accessibility, and transportation concerns. Personal barriers included fear of injury or pain, lack of time, and low self-esteem. Facilitators of participation included social factors (social contacts, participation in society, interaction with others with similar disabilities) and personal beliefs (improved health/fitness, increased self-esteem and self-efficacy, improved skills, and new experiences).

### Strength of Evidence

We did not formally rate risk of bias or strength of evidence. We assessed quality characteristics of included studies and found that approximately half of the included experimental and observational studies did not provide clearly defined inclusion criteria or indicated that participants were “selected”. Many provided little demographic data to allow for a determination of the generalizability of findings. Most studies assessed outcomes using validated questionnaires or objective outcomes measures but, for questionnaires, response rates were less than 50% in 42% of the studies. Of the studies where it would be appropriate to adjust for confounding factors, there was evidence of adjustment in about 50%.

For the qualitative studies, approximately 66% reported congruity between theory and research methods. Nearly all did provide evidence of congruity between the research methods and the research questions, were considered to have adequately represented the participants, and included evidence of ethical approval of the study.

## Applicability of Findings to the VA Population

Our findings have implications for VHA and Veterans in the design, development, implementation, and assessment of adaptive sports activities and programs. There appears to be some evidence that EAAT, in selected populations with PTSD, MS, or CVA who agreed to participate in these programs, can be beneficial. However, there is no information on resource use or the applicability to broader populations of individuals and/or program-specific details. In these populations there is little evidence of harm, though providing for broader populations (eg, those that are not interested in EAAT or with other medical conditions) should be done with caution and should be evaluated. Other sports activities, populations, and settings have a limited empiric base for program development and implementation. Future programs could be derived from existing programs, modified to specific populations and settings, and should undergo evaluation. Because there is general agreement that sport participation should be encouraged, future questions should examine how this can be done in populations with physical challenges that differ from those not requiring sport activity adaptation. Our findings also help categorize and describe important barriers and facilitators to participation that require additional evaluation and incorporation to ensure successful participation at acceptable costs.

## Limitations

Limitations of the available literature include generally low quality of evidence (ie, non-randomized designs, small sample sizes, selected populations) and few studies for many of the adaptive sports and conditions of interest. Disabling conditions were often self-reported and little information was provided about severity of the condition, etiology, comorbidities, or participant demographics. Marked variation in populations, interventions, and outcomes assessment limited data pooling or even semi-quantitative assessment of effect consistency or applicability. Results from EAAT, golf, and fly-fishing programs for individuals with PTSD, MS, or history of CVA may not be generalizable to other sports and other populations. Few studies provided follow-up data to assess whether participation continued and/or whether benefits were maintained.

Participants in the studies included in our review likely had a high level of interest in sports participation (many having participated prior to injury/illness); individuals with severe illness or disability and comorbid conditions were typically excluded from the studies.

Common limitations of studies reporting harms were poor documentation and definition of adverse events. Sample sizes were generally low, and most sports activity participation studies lacked comparators. Potential harms associated with adaptive sports participation in many sports of interest or by many populations of interest are unknown.

## Research Gaps/Future Research

The Adaptive Sports Grant Program, facilitated and managed by NVSP&SE, may provide an opportunity for future research. The Grants Program supports entities with significant experience in managing a large-scale adaptive sports program, including programs affiliated with a National Paralympic Committee or a National Governing Body authorized to provide Paralympic sports and programs in which at least 50 persons with disabilities participate or the eligible participants reside in at least 5 different congressional districts. Federal agencies are encouraged to partner with non-federal entities to jointly create national, regional, and community-based programs that provide adaptive sports activities for disabled Veterans and members of the Armed Forces.

Our findings strongly support the need for rigorous design and outcome evaluation across a spectrum of individuals, health conditions, interventions and settings. Specific recommendations pertaining to the key questions addressed are provided below.

### Key Questions 1 and 2

Future research could address benefits and harms of participation for other adaptive sports and other medical conditions. Studies could be designed to assess whether effectiveness and harms vary by severity of condition, time since disability or diagnosis, skill level of the participants, or their age, gender, or race, and participants could be followed to assess long-term outcomes. Standardized outcome measures should be used to assess a broad range of outcomes including health/wellness, daily functioning, health care utilization, and employment.

Ideally future research into benefit and harms would utilize randomized study designs with appropriate control groups. However, it has been noted that it can be difficult to recruit an adequate sample size and funding for such research may be difficult to obtain.^124^

### Key Question 3

The understanding of barriers to and facilitators of participation would benefit from longitudinal studies that assessed the factors influencing regular participation over an extended period in the individual’s life. Such work could be built into any new regional or national programs. The bulk of evidence reported addressed why people continued to participate in sports versus facilitators to assist individuals in initiating participation.

A gap in the evidence remains concerning the applicability and generalizability to larger populations, including a broader US population including those without an overt interest in sports participation, women, and racial and/or ethnic minorities. Several sports of interest including hand-cycling, para-triathlon, sled hockey, snowboarding, soccer, surfing, wheelchair fencing, and wheelchair lacrosse, were not represented in the literature.

## Conclusions

Evidence for the effectiveness of adaptive sports programs is largely from studies of EAAT in selected populations with a history of PTSD, MS, or CVA. Thus, the strength of evidence to inform developing, implementing, making available, and evaluating the effects of adaptive sports programs or informal adaptive sports participation is low. There is insufficient evidence for other adaptive sports or populations and it is unknown whether findings from a particular sport in a particular population are generalizable. There was little evidence of harms associated with adaptive sports program participation although, again, few adaptive sports or populations of interest were represented in the literature. Barriers to and facilitators of adaptive sports participation were similar across studies reporting on a broader range of medical conditions and adaptive sports. Future research could focus on other adaptive sports and populations, other outcomes including harms, and long-term follow-up to determine if participation is sustained and if benefits are maintained.