# Methods

## Topic Development

The key questions and scope of this review were developed with input from the Operational Partners, Technical Expert Panel, and content experts from the Minneapolis VA Health Care System serving on our project team.

## Search Strategy

We searched MEDLINE from 1995 to July 2018 using Medical Subject Headings (MeSH) and key words for the adaptive sports and medical conditions of interest (Appendix A). We searched EMBASE, SPORTDiscus, and Rehabilitation and Sports Medicine Source using search strategies based on the MEDLINE strategy.

## Study Selection

Citations were entered into Distiller SR (Evidence Partners). Titles were reviewed by a single investigator or research associate. Abstracts of titles identified as potentially eligible were reviewed independently by 2 reviewers with a citation moving to full-text review if either reviewer considered the citation eligible. At the full-text review, agreement of 2 reviewers was needed for study inclusion or exclusion. Disputes were resolved by discussion with input from a third reviewer, if needed.

Due to the large number of citations, we also used the DistillerAI (Artificial Intelligence) feature to complete an AI Audit review of titles. This features screens titles and produces a confidence score from 0 (not confident reference should be included) to 1 (very confident reference should be included) to predict the inclusion/exclusion status of a reference. This prediction is based on a variable test set of included and excluded references identified by a human reviewer. The 850 references identified by Distiller AI were reviewed at the abstract level by a review investigator.

For Key Question 1 and 2 we included intervention studies comparing participation in an adaptive sports program to usual care, no intervention, or other intervention among individuals with a medical condition of interest. We label these as “sports program studies”. To expand the number of potentially eligible studies and provide possible information for the development of future programs, we also included studies of individuals participating in organized adaptive sports activities although the activity wasn’t specifically implemented for the purpose of determining whether participation provided benefits or harms. We label these as “sports activity participation studies” – typically cross-sectional observational studies.

For Key Question 3 we included studies assessing facilitators of and barriers to participation in adaptive sports among individuals with a medical condition of interest.

At all levels of review, the inclusion and exclusion criteria were as follows.

### Inclusion

- Age 18 and older with 1 or more medical conditions of interest (ALS, limb amputation, hearing loss or deafness, MS, PTSD, spinal cord disorder, SCI, CVA, TBI, or visual impairment or blindness);
- Participation in 1 or more adaptive sports of interest (Table 1) at the community level or higher (to include adaptive sports programs that begin during inpatient rehabilitation and continue to an outpatient/community-based phase);
- Reporting an outcome of interest; primary outcomes of interest were a) clinically important changes in health and wellness, daily functioning, self-esteem, perceived competence, community reintegration, participation in social activities, participation in employment, mood//quality of life, and health care utilization; b) harms related to participation in adaptive sports; and c) barriers and facilitators related to adaptive sports participation; secondary outcomes were: a) participation in adaptive sports programs and b) improvement in physical health or PTSD scale scores.

### Exclusion

- Sports programs with modifications of equipment or environment/culture exclusively based on participant age;
- Individual fitness programs or other activities done outside of a program led by a coach or program director (exception – athlete training for competition);
- Study of a sport activity other than pre-defined sports of interest or where >75% of participants are involved in sport not of interest;
- Study of a group of individuals with condition not pre-defined as condition of interest or where >75% do not have a condition of interest;
- Rehabilitation programs with no “sport” component
- Study of “physical activity” levels where physical activity includes items like household work, gardening, volunteering outside the home (ie, studies of physical activity must have included a “sport” component);
- Engineering/modeling studies;
- Human performance laboratory studies.

## Data Abstraction

We abstracted study design and demographic data from eligible studies including medical condition(s), age, gender, and time since injury/diagnosis; adaptive sport; and US Veteran status. We also abstracted primary and secondary outcomes of interest (see Inclusion, above).

## Quality Assessment

We did not formally assess risk of bias of individual studies due to the many study design variants in the included literature. For each included study, we reviewed critical elements of either observational and experimental studies or qualitative studies based on checklists developed by the Joanna Briggs Institute (http://joannabriggs.org/) (Appendix B).

## Data Synthesis

For Key Question 1, tables were developed by outcome and stratified by whether the study reported on an adaptive sport program (“sports program study”) or provided a cross-sectional view of adaptive sport participants (“sports activity participation study”). Subgroups of interest included: time since injury or diagnosis, frequency/duration of participation, age, gender, race, and type and/or severity of disability.

For Key Question 2, we also report outcomes from adaptive sports program and sports activity participation studies.

For Key Question 3, the International Classification of Functioning, Disability, and Health (ICF) model was used to summarize motivators to participation in adaptive sports, facilitators of participation, and barriers to participation.

For all Key Questions, findings were narratively synthesized.

## Rating the Body of Evidence

We did not formally rate the overall quality of the evidence due to heterogeneity of participants, adaptive sports, study designs, and outcomes assessed.

## Peer Review

A draft version of this report was reviewed by content experts as well as clinical leadership. Reviewer comments and our responses are presented in Appendix C and the report was modified.