# Introduction

The term “adaptive sports” is used to describe a sport that has either been adapted specifically for persons with a disability or created specifically for persons with a disability.^1^ For persons with physical disabilities, organized sports can be traced back to the early 1900s. However, opportunities expanded greatly in the post-World War II era when adaptive sports began to be used for rehabilitation of Veterans.^2^ Many of the early programs were in downhill skiing but the range of available sports and opportunities for participation at all levels, from recreational to competitive, has broadened greatly.

Within the Department of Veterans Affairs (VA), the vision of the National Veteran Sports Programs and Special Events (NVSP&SE) office (http://www.va.gov/adaptivesports) is “to be leaders in the provision of adaptive sports and therapeutic arts programs that complement VA’s rehabilitation system of care for Veterans and members of the Armed Forces with disabilities.” The national rehabilitation events are intended to “provide opportunities for Veterans to improve their independence, well-being, and quality of life through adaptive sports and therapeutic arts programs.” The programs offered include the National Veterans Wheelchair Games, the National Veterans Golden Age Games, the National Disabled Veterans Winter Sports Clinic, the National Veterans Summer Sports Clinic, the National Disabled Veterans T.E.E. (Training, Exposure, Experience) Tournament, and the National Veterans Creative Arts Competition and Festival. Partners in the programs include the Paralyzed Veterans of America, the Disabled American Veterans, and the American Legion Auxiliary, along with Veterans Service Organizations, corporate sponsors, individual donors, and community organizations. Veterans training for Paralympic and Olympic sports may qualify for a monthly assistance allowance and the NVSP&SE provides grants to support national or community-based adaptive sports programs with the goal of increasing the availability of adaptive sports activities for Veterans and Service Members.

The purpose of this report is to systematically review the available evidence on the benefits and harms of adaptive sports participation and the barriers to and facilitators of participation. With input from our Operational Partners and Technical Expert Panel members, the scope of the project was limited to the following medical conditions: amyotrophic lateral sclerosis (ALS), limb amputation, hearing loss or deafness, multiple sclerosis (MS), post-traumatic stress disorder (PTSD), spinal cord disorder, spinal cord injury (SCI), cerebrovascular accident/stroke (CVA), traumatic brain injury (TBI), or visual impairment or blindness. Further, the scope was limited to the adaptive sports listed in Table 1. The report was intended to guide the VHA in developing, making available, and evaluating regional and national adaptive sports programs for Veterans that go beyond general recommendations to participate in sports.

Table 1 Adaptive Sports Eligible for Inclusion in Evidence Review

Alpine skiing | Golf | Surfing
Archery | Hand-cycling | Swimming
Athletics/ Track & field | Kayaking/Canoeing | Table Tennis
Billiards | Nordic Skiing | Tennis (including Wheelchair Tennis)
Boccia (Bocci, Bocce) | Para-Triathlon | Weightlifting-Power Lifting
Climbing | Sailing | Wheelchair Basketball
Curling | Shooting | Wheelchair Fencing
Cycling | Sitting Volleyball | Wheelchair Lacrosse
Equine Assisted Activities and Therapies (EAAT) | Sled Hockey | Wheelchair Rugby
Fishing (any type) | Snowboarding
Goalball | Soccer

The key questions for the review were:

Key Question 1. What is the effectiveness of participation in adaptive sports programs among individuals with amyotrophic lateral sclerosis (ALS), limb amputation, hearing loss or deafness, multiple sclerosis (MS), post-traumatic stress disorder (PTSD), spinal cord disorder, spinal cord injury (SCI), stroke/cerebrovascular accident (CVA), traumatic brain injury (TBI), or visual impairment or blindness?

Key Question 1a. Does the effectiveness vary by frequency/duration of adaptive sport program participation?

Key Question 1b. Do particular patient groups (ie, age range, gender, race, time since injury, time involved in adaptive sports, type and/or severity of disability) benefit more than others from adaptive sports participation?

Key Question 2. What are the potential harms of participation in adaptive sports programs among individuals with amyotrophic lateral sclerosis (ALS), limb amputation, hearing loss or deafness, multiple sclerosis (MS), post-traumatic stress disorder (PTSD), spinal cord disorder, spinal cord injury (SCI), stroke/cerebrovascular accident (CVA), traumatic brain injury (TBI), or visual impairment or blindness?

Key Question 3. What are the known facilitators of and barriers to the participation in adaptive sports programs among individuals with amyotrophic lateral sclerosis (ALS), limb amputation, hearing loss or deafness, multiple sclerosis (MS), post-traumatic stress disorder (PTSD), spinal cord disorder, spinal cord injury (SCI), stroke/cerebrovascular accident (CVA), traumatic brain injury (TBI), or visual impairment or blindness?

This review will be used by the Veterans Health Administration (VHA) national program offices for Physical Medicine and Rehabilitation Services, Prosthetic and Sensory Aids Services, Recreation Therapy, and NVSP&SE, as well as the offices under Rehabilitation and Prosthetic Services. The review will inform implementation efforts and enhance efforts to integrate all of the VHA’s rehabilitation programs that incorporate adaptive sports within their treatment plan and the national programs hosted by the NVSP&SE with the goal of advancing Veteran’s access to and the utilization of adaptive sports as part of their ongoing rehabilitation.