# APPENDIX F Motivators of Participation

Figure 1 Motivators to Adaptive Sports Participation