# APPENDIX E Quality Characteristics

Appendix E Table 1 Quality Characteristics of Included Qualitative Studies

Author, year | Congruity between theory and research methods | Congruity between methodology and research questions | Statement locating researcher culturally or theoretically | Participants adequately represented | Evidence of ethical approval | Comments
Bennett 2014^15^; n=28 | Unclear | Yes | No | Yes | Yes | Program was ‘theory-based,’ but no further detail on the theory behind the program or research methods; focus groups
Braganca 2018^20^; n=61 | No | Yes | No | Yes | Yes | Refers to researcher expertise in developing recommendations, but does not describe researchers’ backgrounds or beliefs/values; self-completed questionnaire
Bragaru 2013^23^; n=26 | Yes | Yes | No | Yes | Yes | States no formal ethical permission was needed; interviews
Carin-Levy 2007^29^; n=3 | Yes | Yes | No | Yes | Yes | First author participates in the sport (diving) but does not describe how values/beliefs may influence research; semi-structured telephone interview
Carless 2013^31^; Carless 2014^30^; n=11 | Yes | Yes | Unclear | Yes | Yes | Doesn’t include statement about researcher’s beliefs/values but describes in detail how researcher was embedded in adaptive program (2014); in-person interview
Chard 2016^32^; n=45 | No | Yes | No | Yes | Yes | Telephone interview
Giacobbi 2008^46^; n=26 | Yes | Yes | No | Yes | Yes | Third author is adaptive sports coach but does not describe how values/beliefs may influence research; semi-structured interviews (3^rd^ author did not conduct interviews)
Hawkins 2011^52^; n=10 | Yes | Yes | Unclear | No | Yes | Semi-structured interview questions; 3 researchers independently interpreted interview data; only 10 of 50 program participants agreed to be interviewed
Lape 2017^65^; n=17 | Unclear | Yes | No | Yes | Yes | Used “thematic analysis… that does not rely on a particular theory or epistemology”; focus groups
Litchke 2012^68^; n=5 | No | Yes | No | Yes | Yes | Participants were “purposefully selected” (injured at approximately same time in their lives); semi-structured interview and field observation by investigator and research assistants
Littman 2017^69^; n=27 | No | Yes | No | Yes | Yes | Semi-structured interview
Mowatt 2011^79^; n=67 | Yes | No | No | Yes | Yes | Research questions not stated; a co-investigator also served as program staff; analysis of participant’s letters
Stephens 2012^104^; n=7 | Yes | Yes | No | Yes | Yes | Clearly designed and described study; in-person interviews
Taylor 1996^109^; n=3 | Yes | Yes | No | Yes | No | Series of interviews; author practiced ethnographic interviewing techniques

NA=not applicable

Appendix E Table 2 Quality Characteristics of Included Experimental and Observational Studies

Author, year | Inclusion criteria clearly defined | Subjects and setting described in detail | Strategies to deal with confounding factors | Outcomes measured in valid and reliable way | Evidence of ethical approval | Comments (include questionnaire/survey response rate, if applicable)
Adnan 2001^3^; n=30 | No | Yes | No | No | No | “Selected” participants; study-created questionnaires; adjusted for age only; 41% response in rugby group; unknown response in non-participant group; self-completed assessments
Akbar 2015^4^; n=296 | Yes | Yes | Unclear | Yes | Yes | Unclear if accounted for other factors besides sports participation; had institutional approval and informed consent; blinded clinical assessment
Aydoğ 2006^7^; n=40 | Yes | Yes | NA | Yes | Yes | Informed consent; objective outcome measure
Aytar 2012^8^; n=11 | Yes | Yes | NA | Yes | Yes | Objective balance measure; unclear how disability was rated
Barbin 2008^9^; n=10 | No | No | No | Yes | Yes | Informed consent; limited demographic information; self-report (pre-post design)
Bauerfeind 2015^10^; n=14 | No | Yes | No | Yes | No | Injury registries; unclear how subjective outcome was assessed
Beinotti 2013^11^; n=24 | Yes | No | NA | Yes | Yes | RCT; limited demographic information; concealed allocation; surveys administered by researchers blinded to treatment allocation
Beinotti 2010^12^; n=20 | Yes | No | NA | Yes | Yes | Non-random allocation; surveys administered by therapist with no bonds to the research
Bennett 2017^14^; n=40 | No | Yes | NA | Yes | Yes | Pre-post design
Bennett 2014^13^; n=34 (17 couples) | Yes | Yes | NA | Yes | No | Non-random allocation; self-report; couples completes questionnaires separately
Blauwet 2017; n=134^18^ | Yes | Yes | Yes | Yes | No | Secondary analysis of participant data from program logs
Blauwet 2013^16^; n=149^19^ | Yes | Yes | Yes | No | Yes | Study-created questionnaire (self-report); response rate unclear
Boninger 1996^19^; n=12 | No | Yes | Yes | Yes | Yes | Individuals were invited to participate in training camp so applicability to all wheelchair racers is unknown
Bragaru 2013^22^; n=780 | No | Yes | Yes | Unclear | NA | Secondary analysis of larger database (self-report questionnaire data; 34% response rate; stated no formal ethical permission was needed; participants signed consent form
Bragaru 2015^21^; n=175 | Yes | Yes | Yes | No | Yes | Questionnaire (self-report) not previously validated; 45% response rate
Calsius 2015^25^; D’hooghe 2014^37^; n=9 | No | Yes | NA | Yes | Yes | Pre-post; self-report
Campayo-Piernas 2017^26^; n=21 | No | Yes | NA | Yes | Yes | Objective balance measure
Côté-Leclerc 2017^33^; n=68 | Only for athletes | Only for athletes | NA | Yes | Yes | Control group derived from previous study; matching was inadequate; self-completed assessments
Curtis 1999^34^; n=46 | No | Yes | No | Yes | Yes | 48% response rate to survey; self-report
da Silva 2018^35^; n=24 | No | Yes | NA | Yes | Yes | Groups not matched; researchers administered outcome assessments (questionnaires and performance measures)
Earles 2015^38^; n=16 | No | Yes | NA | Yes | Yes | Pre-post design; consent form and questionnaires administered by research assistant with no role in the therapy
Fiorilli 2013^42^; n=46 | Yes | No | NA | Yes | Yes | Informed consent; 1 researcher administered all assessments
Foreman 1997^43^; n=121 | No | Yes | Yes | Yes | Yes | Informed consent; response rate 60%; self-completed assessments
Fullerton 2003^44^; n=257 | No | No | Yes | No | Yes | Unclear what percentage of responders was identified using the different recruitment approaches; little demographic data; study-created survey; self-reported assessment
Garshick 2016^45^; n=347 | No | Yes | Yes | Yes | Yes | 97% response rate; interview (89%) or self-completed questionnaires
Hammer 2005^49^; n=11 | Yes | Yes | NA | Yes | Yes | Pre-post design; objective and self-report outcomes
Hanson 2001^50^; n=48 | No | No | NA | Yes | No | 100% completed assessments either by interview or in writing (self-completing)
Haykowsky 1999^53^; n=11 | Yes | No | NA | No | Yes | Retrospective data collection (recall), reported injury rates only
Herzog 2018^54^; n=13 | Yes | Yes | NA | Yes | Yes | RCT cross-over design; “randomized by an independent person”; blinded objective outcome assessment
Jaarsma 2014^55^; n=648 | No | No | Yes | No | Yes | Did not separate on-line responses from telephone interview responses; adapted a questionnaire developed for Paralympic athletes; 13% response rate
Jackson 1996^57^; n=33 | No | Yes | NA | Yes | Unclear | Clinical criteria for diagnosis; patients provided informed consent; self-completed questionnaire and clinical assessment
Johnson 2018^58^; n=29 | Yes | No | NA | Yes | Yes | RCT; randomized based on identification number to treatment or wait-list; wait-list group data included in final outcomes data following completion of program; limited demographic information
Jolk 2015^59^; n=7 | Yes | No | NA | Yes | Yes | Pre-post design; limited demographic information; objective outcome measure
Kars 2009^60^; n=105 | Yes | No | No | No | Yes | Study-created questionnaire (self-report via mail); 36% response rate
Kim 2017^61^; n=302 | Yes | Yes | No | No | Yes | Study-created questionnaire (self-report); 53% response rate
Laferrier 2015^63^; n=220 | Yes | Yes | NA | Yes | Yes | Study-created questionnaire (self-report); authors established face validity and reliability
Lanning 2013^64^; n=13 | No | No | NA | Yes | Yes | Pre-post design; limited demographic information
Lastuka 2015^66^; n=131 | No | Yes | Yes | No | No | Study-created survey (unclear how data were collected); no formal pilot; response rate unclear
Lindroth 2015^67^; n=3 | Yes | Yes | NA | Yes | Yes | Pre-post
Lundberg 2011^70^; n=18 | No | No | NA | Yes | Yes | Pre-post; limited demographic information
Malinowki 2018; n=7 | No | Yes | NA | Yes | Yes | Pre-post
McVeigh 2009^76^; n=90 | Yes | Yes | Yes | Yes | No | Verbal consent; telephone interview; 97% response rate
Miki 2012^77^; n=81 | No | Yes | Yes | Yes | Yes | Self-report; response rate not reported
Molik 2010^78^; n=174 | No | No | NA | Yes | Yes | Self-report questionnaire
Muñoz-Lasa 2011^80^; n=27 | Yes | No | NA | Yes | Yes | Non-random allocation; limited demographic information
Muraki 2000^81^; n=169 | No | No | NA | Yes | No | 54% response rate; little demographic data
Nam 2016^82^; n=62 | Yes | Yes | No | No | Yes | Descriptive statistics only; study-created interview/questionnaire based on ICF
Nettleton 2017^83^; n=32 | Yes | Yes | No | Yes | Yes | Self-report; 82% follow-up rate for 1 questionnaire, 78% for second questionnaire
O’Neill 2004^85^; n=33 | No | No | NA | No | No | Study-created questionnaire administered by telephone; also encouraged “free speech responses”; 85% response rate
Perrier 2015^87^; Perrier 2012^86^; n=201 | Yes | Yes | NA | No | Yes | Study-created questionnaire; self-report; 93% response rate for 1^st^ questionnaire; 87% response rate for 2^nd^ questionnaire
Pluym 1997^89^; n=44 | No | Yes | NA | No | No | Study-created questionnaire; in-home interview by 2 interviewers; 96% response
Ponchillia 2002^90^; n=159 | No | Yes | No | Yes | No | Telephone survey of “selected” members; cross-sectional study likely not appropriate to answer research questions about predictors of athletes’ participation and beliefs; study-created survey but authors established validity/reliability
Rauch 2014^92^; n=505 | Yes | Yes | Yes | No | No | Secondary analysis; 27% response rate to full survey; study-created survey
Rogers 2014^93^; n=13 | Yes | Yes | NA | Yes | Yes | Pre-post design
Sá 2012; n=24 | No | No | NA | No | No | Study-created survey (self-report)
Scarpa 2011^95^; n=143 | No | No | Yes | Yes | No | Participants identified through many sources including open on-line; little demographic data; written consent; self-report; we included data from 2 groups: disabled practicing sport and disabled not practicing sport
Schachten 2015^96^; n=14 (7 matched pairs) | No | No | NA | Yes | Yes | Pre-post with matched pairs assigned to intervention and control groups (assignment method not reported); limited demographic information
Shatil 2005^97^; n=18 | Yes | Yes | NA | Yes | Yes | RCT; randomized by selecting 1 of 2 cards (representing the 2 groups); blinded outcome assessment
Silkwood-Sherer 2007^99^; n=15 | Yes | No | NA | Yes | Yes | Pre-post with non-randomized comparison group; limited demographic information; blinding of outcome assessment not reported
Silveira 2017^100^; n=150 | Yes | Yes | Yes | Yes | Yes | Self-report; response rate unknown (individuals at rugby events were invited to participate)
Skordilis 2001^101^; n=243 | No | No | No | Yes | Yes | 27% response rate (mailed questionnaire); distributed questionnaires via coaches of sports clubs so little information on inclusion criteria; informed consent; little demographic data and limited adjustment for confounders
Skučas 2013^102^; n=106 | No | No | NA | Yes | No | Little information about participant identification or demographics; no information on response; rate; unclear if self-report
Sporner 2009^103^; n=132 | Yes | Yes | Yes | Yes | Yes | Response rate unclear (included individuals who volunteered to participate)
Tasiemski 2004^106^; Tasiemski 2005^107^; n=28 | Yes | No | No | Yes | Yes | Piloted questionnaire prior to study; self-report 56% response rate; unclear if demographic data for questionnaire completers or all participants
Tasiemski 2011^105^; n=1034 | Yes | Yes | No | Yes | Yes | 59% response rate; self-report; limited consideration of potential confounders
Tasiemski 2012^108^; n=50 | No | Yes | NA | Yes | No | Little information on identification of study participants
Urbański 2013^110^; n=28 | No | Yes | NA | Yes | No | Telephone survey
Velikonja 2010^112^; n=20 | Yes | No | NA | Yes | Yes | RCT; allocation not reported; limited demographic information; blinded outcome assessment
Vella 2013^113^; n=74 | Yes | Yes | NA | Yes | Yes | Pre-post design; on-line outcomes assessment
Vermöhlen 2017^114^; n=40 | Yes | Yes | NA | Yes | Yes | RCT; adequate sequence generation and allocation concealment; blinded outcome assessment
Wickham 2000^115^; n=24 | No | No | NA | Yes | No | Non-random (control group selected to match intervention group) pre-post; limited demographic information
Wu 2000^116^; n=143 | No | Yes | NA | Yes | No | Subset from larger project; study-created questionnaire piloted and revised before; administration; self-report
Yazicioglu 2012^117^; n=60 | Yes | Yes | NA | Yes | Yes | Self-report
You 2016; n=35^118^ | Yes | Yes | NA | Yes | Yes | Survey (unclear how administered) and clinical assessment; incidence and correlation data
Zoerink 2015^119^; n=11 | No | No | NA | Yes | Yes | Pre-post design; each participants data collected at both time points by same research assistant
Zwierzchowska 2017^120^; n=36 | Yes | Yes | NA | Yes | Yes | Self-report

ICF=International Classification of Functioning, Disability, and Health; NA=not applicable; RCT=randomized controlled trial