# APPENDIX D Evidence Tables

Appendix D Table 1 Study Characteristics – Included Studies

Appendix D Table 2 Adaptive Sports Program Description

Appendix D Table 3 Health and Wellness Outcomes – KQ1

Appendix D Table 4 Daily Functioning Outcomes – KQ1

Appendix D Table 5 Self-Esteem/Perceived Competence – KQ1

Appendix D Table 6 Mental Health (Mood, Depression, Anxiety, PTSD) Outcomes

Appendix D Table 7 Quality of Life

Appendix D Table 8 Community Reintegration/Participation in Social Activities

Appendix D Table 9 Employment