# APPENDIX B Criteria used in Quality Assessment

## Experimental and Observational Studies

(Yes/No/Unclear/Not applicable)

1. Were the criteria for inclusion in the sample clearly defined?
2. Were the study subjects and the setting described in detail?
3. Were strategies to deal with confounding factors stated?
4. Were the outcomes measured in a valid and reliable way?
5. Was there evidence of ethical approval by and appropriate body?

We also noted if outcome assessment was blinded and, for randomized trials, whether randomization and allocation were adequate.

Adapted from:

Moola S, Munn Z, Tufanaro C, . Chapter 7: Systematic reviews of etiology and risk. In Aromataris E, Munn Z (eds) Joanna Briggs Institute Reviewers’s Manual. The Joanna Briggs Institute. 2017. Available from https://reviewersmanual.joannabriggs.org/ Accessed 17 December 2018.

## Qualitative Studies

1. Is there congruity between the stated philosophical perspective and the research methodology?
2. Is there congruity between the research methodology and the research questions or objectives?
3. Is there a statement locating the researcher culturally or theoretically?
4. Are participants, and their voices, adequately represented?
5. Is the research ethical according to current criteria and is there evidence of ethical approval byan appropriate body?

Adapted from:

Lockwood C, Munn Z, Porritt K. Qualitative research synthesis: methodological guidance for systematic reviewers using meta-aggregation. Int J Evid Based Healthc. 2015;13(3):179–187 26262565 .