# APPENDIX A Medline Search Strategy

MEDLINE Search Strategy

1. (skiing or skier).mp. or exp SKIING/
2. (archery or archer).mp.
3. "Track and Field".mp. or exp “Track and Field”/
4. (athletics or “distance racing”).mp.
5. (billiard$ or bocce or bocci).mp.
6. mountaineering.mp. or exp MOUNTAINEERING/
7. (mountain climb$ or hiking).mp.
8. (curling or curler).mp.
9. (bicycling or bicyclist).mp. or exp BICYCLING/
10. (hand-cycl$ or hand cycl$).mp.
11. exp Equine-Assisted Therapy/
12. (equine adj2 therapy).mp.
13. ("horseback riding" or hippotherapy).mp.
14. (fishing or fly-fishing).mp.
15. (goalball or goal-ball).mp.
16. exp GOLF/
17. golf$.mp.
18. (kayak$ or canoe$).mp.
19. (triathlon or para-triathlon).mp.
20. (sailing or sailor).mp.
21. ((trap$ adj2 shoo$) or (skeet$ adj2 shoo$) or sporting clay$).mp.
22. shooting sports.mp.
23. ((sitting or seated) and volleyball).mp.
24. ((sled or sledge) and hockey).mp.
25. snowboar$.mp.
26. power soccer.mp. or exp SOCCER/
27. (surfer or surfing or surfboard).mp.
28. scuba.mp. or exp SWIMMING/
29. table tennis.mp.
30. tennis.mp. or exp TENNIS/
31. (weightlifting or “weight lifting” or “power lifting”).mp. or exp Weight Lifting/
32. wheelchair and (basketball or fencing or lacrosse or rugby or soccer or tennis or sport$ or (marathon$)).mp.
33. (sport$ adj5 (practice or participa$)).ti,ab.
34. 1 or 2 or 3 or 4 or 5 or 6 or 7 or 8 or 9 or 10 or 11 or 12 or 13 or 14 or 15 or 16 or 17 or 18 or 19 or 20 or 21 or 22 or 23 or 24 or 25 or 26 or 27 or 28 or 29 or 30 or 31 or 32 or 33
35. amyotrophic lateral sclerosis.mp. or exp Amyotrophic Lateral Sclerosis/
36. (amputation or amputee).mp. or exp Amputation/ or exp Amputation, Traumatic/
37. ((limb and deficien$) or (limb and disabilit$) or (artificial and limb) or (prosthe$ and limb)).mp.
38. ((hearing adj2 loss) or deaf or hearing impair$).mp. or exp Hearing Loss/
39. multiple sclerosis.mp. or exp Multiple Sclerosis/
40. exp Stress Disorders, Post-Traumatic/
41. (post-traumatic stress disorder or posttraumatic stress disorder).mp.
42. exp Spinal Cord Injuries/
43. (spinal cord injur$ or spinal cord disorder$).mp.
44. exp STROKE/
45. (“cerebral vascular accident” or “cerebrovascular accident”).mp.
46. traumatic brain injur$.mp. or exp Brain Injuries, Traumatic/
47. blindness.mp. or exp BLINDNESS/
48. (visua$ and (disab$ or impair$)).mp.
49. (sensory and (disab$ or impair$)).mp.
50. ((mobility and disabil$) or (mobility and impair$)).mp.
51. (tetraplegi$ or quadriplegi$ or paraplegi$).mp.
52. exp Quadriplegia/ or exp Paraplegia/
53. (physical$ and (disab$ or challeng$)).mp.
54. 35 or 36 or 37 or 38 or 39 or 40 or 41 or 42 or 43 or 44 or 45 or 46 or 47 or 48 or 49 or 50 or 51 or 53
55. 34 and 54
56. “winter sports clinic”.ti,ab.
57. “summer sports clinic”.ti,ab.
58. “wheelchair games”.ti,ab.
59. (paralympi$ or para-olympi$ or para-sport$ or parasport$).mp.
60. exp Sports for Persons with Disabilities/
61. ((adapted or adaptive) adj5 (sport$ or recreation or activit$ or exercise)).mp.
62. “special olympi$”.mp.
63. (disabl$ adj3 sport$).mp.
64. (disabl$ adj2 athlet$).mp.
65. 56 or 57 or 58 or 59 or 60 or 61 or 62 or 63 or 64
66. 55 or 65
67. limit 66 to (english language and yr=“1995 -Current”)