# REFERENCES

1 Siegel RL, Giaquinto AN, Jemal A. Cancer statistics, 2024. CA Cancer J Clin. Jan–Feb 2024;74(1):12–49. doi:10.3322/caac.21820 38230766
2 U.S. Cancer Statistics Working Group. U.S. Cancer Statistics Data Visualizations Tool. U.S. Department of Health and Human Services, Centers for Disease Control and Prevention and National Cancer Institute. Updated June 2024. Accessed 07/15/2024, 2024. https://www.cdc.gov/cancer/dataviz
3 Jonas DE, Reuland DS, Reddy SM, . Screening for Lung Cancer With Low-Dose Computed Tomography: Updated Evidence Report and Systematic Review for the US Preventive Services Task Force. JAMA. Mar 9 2021;325(10):971–987. doi:10.1001/jama.2021.0377 33687468
4 US Preventive Services Task Force. US Preventive Services Task Force Issues Final Recommendation on Screening for Colorectal Cancer. Accessed 10/02/2024, https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/colorectal-cancer-screening
5 Howard DH, Richards TB, Bach PB, Kegler MC, Berg CJ. Comorbidities, smoking status, and life expectancy among individuals eligible for lung cancer screening. Cancer. Dec 15 2015;121(24):4341–7. doi:10.1002/cncr.29677 26372542
6 Centers for Medicare & Medicaid Services. Screening for lung cancer with low dose computed tomography (LDCT). CMS. Accessed 10/15/2024, 2024. https://www.cms.gov/medicare-coverage-database/view/ncacal-decision-memo.aspx?proposed=N&ncaid=304
7 Alishahi Tabriz A, Neslund-Dudas C, Turner K, Rivera MP, Reuland DS, Elston Lafata J. How Health-Care Organizations Implement Shared Decision-making When It Is Required for Reimbursement: The Case of Lung Cancer Screening. Chest. 2021;159(1):413–425. Comment in: Chest. 2021 Jan;159(1):23–24 PMID: 33422199 [https://www.ncbi.nlm.nih.gov/pubmed/33422199]. doi:10.1016/j.chest.2020.07.078 32798520
8 Elwyn G, Laitner S, Coulter A, Walker E, Watson P, Thomson R. Implementing shared decision making in the NHS. BMJ. Oct 14 2010;341:c5146. doi:10.1136/bmj.c5146 20947577
9 International Patient Decision Aid Standards Collaboration. What are Patient Decision Aids? Web Page. International Patient Decision Aid Standards Collaboration. Updated 03/13/2024. Accessed 09/24/24, 2024. http://ipdas.ohri.ca/what.html
10 Department of Veterans Affairs. VA Benefits & Health Care Utilization. Updated 10/30/2023. https://www.va.gov/VETDATA/docs/pocketcards/fy2023q4_alteration.pdf
11 Kinsinger LS, Anderson C, Kim J, . Implementation of Lung Cancer Screening in the Veterans Health Administration. JAMA Intern Med. Mar 1 2017;177(3):399–406. doi:10.1001/jamainternmed.2016.9022 28135352
12 Sterne JAC, Savovic J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Aug 28 2019;366:l4898. doi:10.1136/bmj.l4898 31462531
13 Joanna Briggs Institute. Checklist for Cohort Studies: Critical Appraisal tools for use in JBI Systematic Reviews. Accessed 10/02/2024, https://jbi.global/critical-appraisal-tools#:~:text=JBI%E2%80%99s%20Evidence%20Synthesis%20Critical%20Appraisal%20Tools
14 Barker TH HN, Aromataris E, Stone JC, Leonardi-Bee J, Sears K, . The revised JBI critical appraisal tool for the assessment of risk of bias quasi-experimental studies. JBI Evid Synth. 2024 2016:2019–05. doi:22(3):378–88
15 Critical Appraisal Skills Programme. CASP Qualitative Studies Checklist. Online. Accessed 10/02/2024, https://casp-uk.net/casp-tools-checklists/qualitative-studies-checklist/
16 Damschroder LJ, Reardon CM, Widerquist MAO, Lowery J. The updated Consolidated Framework for Implementation Research based on user feedback. Implement Sci. Oct 29 2022;17(1):75. doi:10.1186/s13012-022-01245-0 36309746
17 Guyatt GH, Oxman AD, Kunz R, . What is “quality of evidence” and why is it important to clinicians? BMJ. May 3 2008;336(7651):995–8. doi:10.1136/bmj.39490.551019.BE 18456631
18 Han PKJ, Lary C, Black A, . Effects of Personalized Risk Information on Patients Referred for Lung Cancer Screening with Low-Dose CT. Medical decision making : an international journal of the Society for Medical Decision Making. 2019;39(8):950–961. doi:10.1177/0272989X19875966 31631776
19 Schapira MM, Hubbard RA, Whittle J, . Lung Cancer Screening Decision Aid Designed for a Primary Care Setting: A Randomized Clinical Trial. JAMA network open. 2023;6(8):e2330452. doi:10.1001/jamanetworkopen.2023.30452 37647070
20 Tanner NT, Banas E, Yeager D, Dai L, Hughes Halbert C, Silvestri GA. In-person and Telephonic Shared Decision-making Visits for People Considering Lung Cancer Screening: An Assessment of Decision Quality. Chest. Jan 2019;155(1):236–238. doi:10.1016/j.chest.2018.07.046 30616725
21 Schapira MM, Chhatre S, Prigge JM, . A Veteran-Centric Web-Based Decision Aid for Lung Cancer Screening: Usability Analysis. JMIR formative research. 2022;6(4):e29039. doi:10.2196/29039 35394433
22 Wiener RS, Koppelman E, Bolton R, . Patient and Clinician Perspectives on Shared Decision-making in Early Adopting Lung Cancer Screening Programs: a Qualitative Study. Journal of general internal medicine. 2018;33(7):1035–1042. Comment in: J Gen Intern Med. 2018 Jul;33(7):989–990 PMID: 29736754 [https://www.ncbi.nlm.nih.gov/pubmed/29736754]. doi:10.1007/s11606-018-4350-9 29468601
23 Crothers K, Kross EK, Reisch LM, . Patients’ Attitudes Regarding Lung Cancer Screening and Decision Aids. A Survey and Focus Group Study. Annals of the American Thoracic Society. 2016;13(11):1992–2001. Comment in: Ann Am Thorac Soc. 2016 Nov;13(11):1887-1889 PMID: 27831805 [https://www.ncbi.nlm.nih.gov/pubmed/27831805].27652509
24 IPDAS. International Patient Decision Aid Standards Collaboration. 2024. http://ipdas.ohri.ca/
25 Fagan HB, Fournakis NA, Jurkovitz C, . Telephone-Based Shared Decision-making for Lung Cancer Screening in Primary Care. Journal of cancer education : the official journal of the American Association for Cancer Education. 2020;35(4):766–773. doi:10.1007/s13187-019-01528-z 31069714
26 Bittner Fagan H, Jurkovitz C, Zhang Z, . Primary care outreach and decision counseling for lung cancer screening. Journal of medical screening. 2023:9691413231213495. doi:10.1177/09691413231213495
27 DiCarlo M, Myers P, Daskalakis C, . Outreach to primary care patients in lung cancer screening: A randomized controlled trial. Preventive medicine. 2022;159:107069. doi:10.1016/j.ypmed.2022.107069 35469777
28 Ito Fukunaga M, Balwan A, Janis JA, Gutheil C, Yahwak J, Han PKJ. Pilot Study of an Encounter Decision Aid for Lung Cancer Screening. Journal of cancer education : the official journal of the American Association for Cancer Education. 2022;37(4):1161–1165. doi:10.1007/s13187-020-01933-9 33411250
29 Kukhareva PV, Li H, Caverly TJ, . Implementation of Lung Cancer Screening in Primary Care and Pulmonary Clinics: Pragmatic Clinical Trial of Electronic Health Record-Integrated Everyday Shared Decision-Making Tool and Clinician-Facing Prompts. Chest. 2023;164(5):1325–1338. doi:10.1016/j.chest.2023.04.040 37142092
30 Percac-Lima S, Ashburner JM, Rigotti NA, . Patient navigation for lung cancer screening among current smokers in community health centers a randomized controlled trial. Cancer medicine. 2018;7(3):894–902. doi:10.1002/cam4.1297 29464877
31 Sferra SR, Cheng JS, Boynton Z, . Aiding shared decision making in lung cancer screening: two decision tools. Journal of public health (Oxford, England). 2021;43(3):673–680. doi:10.1093/pubmed/fdaa063 32672329
32 Flores EJ, Neil JM, Tiersma KM, . Feasibility and Acceptability of a Collaborative Lung Cancer Screening Educational Intervention Tailored for Individuals With Serious Mental Illness. Journal of the American College of Radiology : JACR. 2021;18(12):1624–1634. doi:10.1016/j.jacr.2021.07.010 34375628
33 Mazzone PJ, Tenenbaum A, Seeley M, . Impact of a Lung Cancer Screening Counseling and Shared Decision-Making Visit. Chest. 2017;151(3):572–578. doi:10.1016/j.chest.2016.10.027 27815154
34 Sakoda LC, Meyer MA, Chawla N, . Effectiveness of a Patient Education Class to Enhance Knowledge about Lung Cancer Screening: a Quality Improvement Evaluation. Journal of cancer education : the official journal of the American Association for Cancer Education. 2020;35(5):897–904. doi:10.1007/s13187-019-01540-3 31073869
35 Walsh JME, Karliner L, Smith A, . LungCARE: Encouraging Shared Decision-Making in Lung Cancer Screening-a Randomized Trial. Journal of general internal medicine. 2023;38(14):3115–3122. doi:10.1007/s11606-023-08189-1 37653203
36 Brehaut JC, O’Connor AM, Wood TJ, . Validation of a decision regret scale. Med Decis Making. Jul–Aug 2003;23(4):281–92. doi:10.1177/0272989X03256005 12926578
37 Webster M, Whealan J, Williams RM, . The tobacco quitline setting as a teachable moment: The Educating Quitline Users About Lung (EQUAL) cancer screening randomized trial. Translational behavioral medicine. 2023;13(10):736–747. doi:10.1093/tbm/ibad049 37616531
38 Lau YK, Bhattarai H, Caverly TJ, . Lung Cancer Screening Knowledge, Perceptions, and Decision Making Among African Americans in Detroit, Michigan. American journal of preventive medicine. 2021;60(1):e1–e8. doi:10.1016/j.amepre.2020.07.004 33341184
39 Lau YK, Caverly TJ, Cao P, . Evaluation of a Personalized, Web-Based Decision Aid for Lung Cancer Screening. American journal of preventive medicine. 2015;49(6):e125–9. doi:10.1016/j.amepre.2015.07.027 26456873
40 Hoffman AS, Hempstead AP, Housten AJ, . Using a Patient Decision Aid Video to Assess Current and Former Smokers’ Values About the Harms and Benefits of Lung Cancer Screening With Low-Dose Computed Tomography. MDM policy & practice. 2018;3(1):2381468318769886. doi:10.1177/2381468318769886 30288444
41 Volk RJ, Lowenstein LM, Leal VB, . Effect of a Patient Decision Aid on Lung Cancer Screening Decision-Making by Persons Who Smoke: A Randomized Clinical Trial. JAMA network open. 2020;3(1):e1920362. doi:10.1001/jamanetworkopen.2019.20362 32003822
42 Volk RJ, Linder SK, Leal VB, . Feasibility of a patient decision aid about lung cancer screening with low-dose computed tomography. Preventive medicine. 2014;62:60–3. doi:10.1016/j.ypmed.2014.02.006 24518006
43 Strong A, Renaud M. Using Social Media as a Platform for Increasing Knowledge of Lung Cancer Screening in High-Risk Patients. Journal of the advanced practitioner in oncology. 2020;11(5):453–459. doi:10.6004/jadpro.2020.11.5.2 32974070
44 Studts JL, Thurer RJ, Brinker K, Lillie SE, Byrne MM. Brief Education and a Conjoint Valuation Survey May Reduce Decisional Conflict Regarding Lung Cancer Screening. MDM policy & practice. 2020;5(1):2381468319891452. doi:10.1177/2381468319891452 31976372
45 Clark SD, Reuland DS, Brenner AT, Jonas DE. Effect of Incidental Findings Information on Lung Cancer Screening Intent: a Randomized Controlled Trial. Journal of general internal medicine. 2022;37(14):3676–3683. doi:10.1007/s11606-022-07409-4 35113322
46 Carter-Harris L, Comer RS, Slaven Ii JE, . Computer-Tailored Decision Support Tool for Lung Cancer Screening: Community-Based Pilot Randomized Controlled Trial. Journal of medical Internet research. 2020;22(11):e17050. doi:10.2196/17050 33141096
47 Reuland DS, Cubillos L, Brenner AT, Harris RP, Minish B, Pignone MP. A pre-post study testing a lung cancer screening decision aid in primary care. BMC medical informatics and decision making. 2018;18(1):5. doi:10.1186/s12911-018-0582-1 29325548
48 Robichaux C, Anderson M, Freese R, Stately A, Begnaud A. Lung Cancer Screening Outreach Program in an Urban Native American Clinic. Journal of primary care & community health. 2023;14:21501319231212312. doi:10.1177/21501319231212312
49 Sharma A, Bansal-Travers M, Celestino P, . Using a Smoking Cessation Quitline to Promote Lung Cancer Screening. American journal of health behavior. 2018;42(6):85–100. doi:10.5993/AJHB.42.6.9
50 Fraenkel L, Peters E, Tyra S, Oelberg D. Shared Medical Decision Making in Lung Cancer Screening: Experienced versus Descriptive Risk Formats. Medical decision making : an international journal of the Society for Medical Decision Making. 2016;36(4):518–25. doi:10.1177/0272989X15611083 26442791
51 Holmes-Rovner M, Kroll J, Schmitt N, . Patient satisfaction with health care decisions: the satisfaction with decision scale. Med Decis Making. Jan–Mar 1996;16(1):58–64. doi:10.1177/0272989X9601600114 8717600
52 Lowenstein LM, Richards VF, Leal VB, . A brief measure of Smokers’ knowledge of lung cancer screening with low-dose computed tomography. Prev Med Rep. Dec 2016;4:351–6. doi:10.1016/j.pmedr.2016.07.008 27512650
53 Studts JL, Hirsch EA, Silvestri GA. Shared Decision-Making During a Lung Cancer Screening Visit: Is It a Barrier or Does It Bring Value? Chest. 2023;163(1):251–254. doi:10.1016/j.chest.2022.07.024 35940213
54 Goodwin JS, Li S. Clinician and Patient Characteristics Associated With Lung Cancer Screening Following a Shared Decision-making Visit. JAMA network open. 2020;3(10):e2021197. doi:10.1001/jamanetworkopen.2020.21197 33074322
55 Herbst AN, McCullough MB, Wiener RS, Barker AM, Maguire EM, Fix GM. Proactively tailoring implementation: the case of shared decision-making for lung cancer screening across the VA New England Healthcare Network. BMC health services research. 2023;23(1):1282. doi:10.1186/s12913-023-10245-9 37993840
56 Lowery J, Fagerlin A, Larkin AR, Wiener RS, Skurla SE, Caverly TJ. Implementation of a Web-Based Tool for Shared Decision-making in Lung Cancer Screening: Mixed Methods Quality Improvement Evaluation. JMIR human factors. 2022;9(2):e32399. doi:10.2196/32399 35363144
57 Martinez MC, Stults CD, Li J. Provider and patient perspectives to improve lung cancer screening with low-dose computed tomography 5 years after Medicare coverage: a qualitative study. BMC primary care. 2022;23(1):332. doi:10.1186/s12875-022-01925-2 36539693
58 Reese TJ, Schlechter CR, Kramer H, . Implementing lung cancer screening in primary care: needs assessment and implementation strategy design. Translational behavioral medicine. 2022;12(2):187–197. doi:10.1093/tbm/ibab115 34424342
59 Abubaker-Sharif M, Shusted C, Myers P, Myers R. Primary Care Physician Perceptions of Shared Decision Making in Lung Cancer Screening. Journal of cancer education : the official journal of the American Association for Cancer Education. 2022;37(4):1099–1107. doi:10.1007/s13187-020-01925-9 33230673
60 Melzer AC, Golden SE, Ono SS, Datta S, Crothers K, Slatore CG. What Exactly Is Shared Decision-Making? A Qualitative Study of Shared Decision-Making in Lung Cancer Screening. Journal of general internal medicine. 2020;35(2):546–553. doi:10.1007/s11606-019-05516-3 31745852
61 Boulate D, Fidelle M, Caramella C, . Epidemiological Study to Assess the Prevalence of Lung Cancer in patients with smoking-associated atherosclerotic cardiovascular diseases: PREVALUNG study protocol. BMJ open. 2022;12(12):e067191. doi:10.1136/bmjopen-2022-067191
62 Sepucha KR, Abhyankar P, Hoffman AS, . Standards for UNiversal reporting of patient Decision Aid Evaluation studies: the development of SUNDAE Checklist. BMJ Qual Saf. May 2018;27(5):380–388. doi:10.1136/bmjqs-2017-006986
63 Force USPST, Davidson KW, Mangione CM, . Collaboration and Shared Decision-Making Between Patients and Clinicians in Preventive Health Care Decisions and US Preventive Services Task Force Recommendations. JAMA. Mar 22 2022;327(12):1171–1176. doi:10.1001/jama.2022.3267 35315879