# ACKNOWLEDGMENTS

The authors are grateful to the external peer reviewers for their review and careful critique of this project.

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Christopher Slatore, MD
  Chief Consultant
  National Center for Lung Cancer Screening

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Angela Fagerlin, PhD
  Associate Vice President for Faculty, Health Sciences
  Professor and Chair, University of Utah Intermountain Healthcare Department of Population Health Sciences
  Jon M. Huntsman Presidential Endowed Chair
  Research Scientist, Salt Lake City VA Informatics
  Decision-Enhancement and Analytic Sciences
- Scott Pawlikowski, MD
  Director, Improvement and Innovation
  VACO Office of Primary Care
- Robert Volk, PhD
  Professor, Department of Health Services
  Research, Division of OVP, Cancer Prevention and Population Sciences, The University of Texas MD Anderson Cancer Center
- Renda Wiener, MD, MPH
  Deputy Chief Consultant, National Center for Lung Cancer Screening
  Associate Director, Center for Healthcare Organization & Implementation Research (CHOIR)
  VA Boston Healthcare System