# DISCUSSION

Lung cancer is the most common nondermatologic malignancy in adults and the leading cause of cancer-related death in the US. Screening with low-dose CT scanning reduces lung cancer mortality and is recommended by the USPSTF and the VA. However, LCS rates are low. Concerns remain that screening harms and burden, as well as referral of patients unlikely to adhere to initial or subsequent screening and follow-up for evaluation and treatment of abnormal findings, may limit net benefit. Thus, prior to LCS, clinicians are encouraged to provide patients with information about risks and benefits including the importance of screening and abnormal test evaluation adherence and smoking cessation and to solicit and support patient preferences and values in the decision-making process (ie, SDM). However, the effectiveness, harms, and burden of LCS SDM or the preferred approaches for SDM are not well understood. In particular, the harms and burden, including time, IT support, and resource allocation/usage of SDM for all potentially eligible individuals for LCS, were not reported. Additional author-defined harms were not reported. We categorized various measures of patient anxiety or decisional regret as harms. Our systematic review found that studies varied markedly in methodological characteristics and many had notable limitations to their rigor, replicability, and clinical applicability. Inconsistency in study designs (including sample sizes and duration), interventions, comparators, delivery modes and timing, and outcomes present important challenges to systematic reviewers, SDM researchers, clinicians, policymakers, and patients. Moreover, few studies provided information about whether their interventions met CMS criteria for SDM. Despite these limitations, the following observations and conclusions were possible:

## Key Findings

► A wide range of lung cancer screening communication strategies and information tools were studied across clinic settings/encounters, delivery approaches, and targeted individuals.
  ○ Authors often did not provide adequate information about the studied tools to determine if they met criteria for a patient decision aid rather than an “information tool.”
  ○ Strategies were characterized as health care professional-facing (used in clinic to guide discussion) or patient-facing (inform patient prior to or during visit but not guide discussion).
    ■ Within health care professional-facing: tools were meant to be used by a clinician or LCS navigator.
    ■ Within patient-facing: strategies were used prior to, or during a scheduled SDM visit, or to generate a SDM visit.
  ○ Some strategies combined SDM tools with care coordinators or navigators.
  ○ The most studied tool (k= 7) was a 5–15-minute decision aid available as print or web-based in English, Spanish, and Chinese language (www.shouldiscreen.com). The current tool includes the 2021 USPSTF recommendations and content.
► While most studies reported on knowledge, few addressed receipt of initial, or follow-up, LCS, adherence to evaluation and treatment of abnormal LCS findings, information quality, concordance of the screening decision with patient values, or patients’ decisional conflict, regret, or distress/anxiety.
  ○ Studies did not report on many other outcomes of interest including smoking behaviors; resource allocations/usage (eg, clinician time, clinical staff/patient time, medical media support, IT support); cost or cost effectiveness.
  ○ Studies did not report on fidelity (how well the intervention was delivered).
► SDM strategies and tools may increase LCS participation, may have acceptable information quality, and may not increase decisional conflict/regret. A decision aid may be superior to an educational tool, and the choice of decision aid may not impact uptake.
  ○ Decision aid selection should be guided by the population and setting of interest.
► Limitations and inconsistency in study design and aim, interventions, comparators, outcome measures, and risks of bias precluded synthesizing evidence or deriving conclusive statements on most interventions/outcomes, resulting in low to very low certainty of evidence.
  ○ There was little to no evidence on whether SDM effectiveness varied by patient (age, sex, race/ethnicity, smoking status, comorbidities, education) or clinic characteristics (primary care, prevention, smoking cessation clinics or public forums).
► Barriers to LCS SDM implementation include resource availability, particularly time constraints; patients’ reticence and lack of engagement with SDM; and patients’ negative response to SDM. Facilitators included use of a decision aid during the SDM encounter.
► Based on implementation studies conducted in VHA, implementation facilitators include: a clinical culture receptive to SDM; available resources including time and tools; prioritization among other clinic demands and expectations; and innovation among deliverers and recipients.
► Future research is needed to enhance LCS and SDM implementation. Areas include: developing methods for accurate, efficient, and effective detection of individuals eligible for LCS and follow-up; avoiding unnecessary or harmful referral of ineligible individuals and those unlikely to adhere to initial or follow-up LCS or subsequent evaluations; creating efficient, accurate, effective, and pragmatic SDM strategies that are adaptable to a variety of settings and patients while reducing patient, clinician, and health system burden; enhancing smoking cessation; and ensuring equity in LCS and communication strategies across patient and clinical settings.

## Study Design Variation

This review identified RCTs, CCTs, and pre-post and cohort studies. The degree to which efficacy or comparative effectiveness can be assessed with pre-post and cohort studies is limited. By its nature, the pre-post design does not allow for comparison between an intervention and comparator group for important outcomes such as receipt of LCS or adherence.

## Included Interventions

There are several tools that have been developed for SDM. Unfortunately, there was inconsistency in reporting/description of these tools in the literature, so classifying these tools into categories of patient decision aid or educational tool relied on author report or was not possible. A repository of published tools that SDM researchers could review and critique would be very helpful in understanding what has been tested in these at-risk populations. Access to the tools would also allow for accurate classification of the tool as a patient decision aid or educational tool. It would facilitate assessment of whether one tool is interchangeable with another and how applicable study findings are to SDM in general and not specific to the tool utilized by the study. Some studies did not base their interventions on recognized criteria for SDM. Furthermore, some studies included additional outreach beyond SDM tools such as care coordinators or patient navigators to facilitate screening scheduling, attendance, and follow-up.

## Comparators

As there are a multitude of tools that have been developed for SDM, this further complicates synthesizing the available evidence as authors may choose to compare to any of these tools, the same tool, or no tool/usual care. Unless there is agreement that these tools are interchangeable—or a subset of tools is selected for further evaluation—identifying the most effective tool will remain challenging.

## Primary Outcomes/Outcomes Of Interest

Knowledge is the outcome most reported. However, outcomes ranked highest by our content experts and TEP were infrequently reported. Adherence to subsequent screening, an outcome of great interest, was only captured by a single study. This variation in outcome reporting is further compounded by authors’ use of study-developed or unique methods of outcome measurement. Examples of this variation were the measures used to assess knowledge and quality of communication. Some studies used validated measures, whereas others used a single question to ascertain a participant’s understanding of LCS and whether the participant felt the SDM tool was of good quality.

## Mode of Delivery/Timing

Studies varied widely in when and how SDM interventions were delivered, and as a result, the optimal timing and mode of administration of SDM remains unclear.

## Applicability of Findings

Many studies were conducted in research settings with a study coordinator, highly refined entry criteria, and filtering of many potentially eligible individuals and analysis of responders. Whether results from these studies will directly apply to most clinical settings is not well known, especially when including our findings evaluating SDM barriers and facilitators.

## Policy Implications (VA Specific)

A single study assessed a tool developed for the VA LCS demonstration project that began in 2013 and is referenced in VA guidance for LCS (https://www.prevention.va.gov/preventing_diseases/screening_for_lung_cancer.asp).^23^ That study was not conducted in a Veteran population. The 2 available studies that were conducted in Veteran populations examined different tools from the one referenced in the VA guidance.^19,20^ Qualitative research suggested that Veterans and health care providers felt that VA culture was receptive to LCS SDM but that competing demands and time needed to conduct SDM were barriers to implementation.

Future research should be conducted in VHA to evaluate the effects, including the feasibility and barriers, of tools and strategies for LCS SDM. These tools and strategies, including the currently available VA tool, should be administered in various formats, clinical settings, and population targets. Studies should be designed with current clinical practice and procedures in mind so results are generalizable to primary care or prevention clinics, including those embedded in large medical centers as well as those in community-based outpatient clinics (CBOCs).

## Barriers and Facilitators

While implementation studies identified barriers, reducing these barriers could enhance SDM implementation into health care. Many of the identified barriers and facilitators pertained to available resources and time availability.

Given that LCS is recommended and underutilized among eligible individuals, the most important facilitator for LCS uptake may not be to define and refine the “best SDM” method. Rather, a critical facilitator is enhancing accurate and efficient identification, communication, and referral of eligible individuals for LCS, and ensuring LCS adherence and follow-up. As noted in a qualitative study conducted in VA: “The data supports so strongly that [LCS] is beneficial, that is doesn’t seem like there’s much of a decision.”^55^ Reducing barriers related to available resources, prioritization among other clinic demands and expectations, and innovation among both the deliverers and the recipients are needed. As a corollary, strategies are needed to avoid unnecessary or even harmful referral of ineligible individuals or those unlikely to adhere or follow-up.

## LIMITATIONS

While the primary limitations to our findings are those inherent to the existing evidence, our review was limited to English language publications. However, the focus of this report is LCS SDM in the US. Potential differences in patients, disease etiology, and screening requirements from non-English language countries (and English language studies conducted outside the US) have lower applicability to US settings. Thus, limiting our inclusion to English language is unlikely to change findings.

## FUTURE RESEARCH

The current review highlights limitations of the LCS SDM evidence base. Standardization of outcome measures, greater transparency regarding tool domains and content, use of study designs that allow for assessment of efficacy and comparative effectiveness for all outcomes, and replicability of findings across populations, interventions, comparators, and settings would improve evidence certainty.^62^

Research is needed to enhance implementation by identifying and reducing barriers and encouraging facilitators to SDM and LCS. These can be targeted at several links in the screening chain including: 1) identifying individuals eligible and not eligible for screening; 2) efficiently and effectively communicating accurate information on LCS benefits and harms to patients in busy primary care settings; 3) understanding patient concerns about LCS and whether these vary by race/ethnicity, sex, geographic location, access to care, or social determinants of health; 4) facilitating scheduling of LCS appointments, tracking results, adherence to subsequent screening, and evaluation of abnormal findings; 5) evaluating when is the best time to present a decision support intervention (before or during the clinic visit) and whether patient versus clinician-based tools are most effective and feasible; 6) not referring or recommending LCS among individuals unlikely to benefit or adhere to LCS or follow-up evaluations; 7) improving tobacco cessation. Whether tools/strategies should be “patient facing” or “provider facing”; delivered by telehealth or in-person; print, or web-based; and whether they differ by patient characteristics (race/ethnicity, sex, education, sociodemographic factors) are largely unknown and may vary by feasibility, resource availability, and health care settings. Research could include determining knowledge elements most useful for informing screening decisions and ensuring SDM aids use validated instruments and include values/preference clarification components.

Finally, the requirement to conduct SDM for lung cancer screening remains unique among all cancer screening recommendations that receive an “A” or “B” recommendation by the USPSTF (ie, at least moderate certainty that implementing the recommended strategy results in at least moderate net benefit). Despite differences in specific screening strategies, benefits, and harms, other A/B recommendations do not require or strongly encourage that clinicians, health systems, and patients first engage in SDM rather than recommend screening. Lessons could be learned by examining screening implementation for other cancers with similar screening test frequency, adherence importance, and certainty of net benefit, such as mammography for breast cancer or stool-based testing or direct visualization testing for colorectal cancer (both have much higher screening rates while also noting the importance of requiring adherence to the full screening and follow-up cascade to be effective).^63^ If a main goal of LCS is to increase LCS among eligible individuals, reducing barriers to the screening process is needed and may include reducing barriers inherent with formal SDM in eligible individuals. This includes improving efficiencies and reducing patient, clinician, and health system burden of SDM implementation.

Consistent with a USPSTF “B” recommendation, clinicians should generally recommend LCS in eligible individuals with a discussion of the rationale but understand that some patients will choose not to receive LCS. Additionally, the USPSTF and CMS raise concerns that the general US population eligible for lung cancer screening may be less likely to benefit from early detection compared with participants enrolled in LCS RCTs, mainly because they face a higher risk of death from competing causes such as heart disease and stroke.^5–7^ Both the USPSTF and CMS emphasize the importance of adherence to the screening process including willingness to undergo curative treatment. However, these concerns are not unique to LCS and may reflect issues regarding resource requirements for low-dose CT scanning and tracking, follow-up, and treatment of abnormal findings not fully considered in the screening guideline net benefit calculations. Thus, future research should better assess competing risk and adherence in individuals deemed eligible for LCS based on age and smoking history.

## CONCLUSIONS

Strategies that include SDM tools, and possibly care coordinators or patient navigators, may increase LCS participation, have acceptable information quality, and do not increase decisional conflict/regret. A decision aid may be superior to an educational tool, and the choice of decision aid may not impact uptake. Variation in study design, LCS tools and strategies, comparator, delivery mode and timing, and outcomes presents challenges in evaluation and implementation. Few studies provided sufficient information about whether the tool or process met criteria to be classified as a decision aid or included information required by Medicare. While most studies reported on knowledge, comparatively few assessed receipt of initial or adherence to follow-up LCS, information quality, concordance of the screening decision with patient values, or patients’ decisional conflict, regret, or distress/anxiety. There was little to no evidence on whether effects varied by patient (age, sex, race/ethnicity, smoking status, comorbidities, education) or clinic characteristics (primary care, prevention, smoking cessation clinics or public forums).

Barriers to SDM include resource availability, especially time constraints, patients’ reticence and lack of engagement with SDM, and patients’ negative response to SDM. Facilitators include use of a decision aid during the SDM encounter. Research is needed to identify the most effective SDM tools and strategies, particularly those that are low burden and adaptable to different settings and patients, reduce barriers to identify individuals eligible for LCS, enhance LCS adherence and follow-up, promote smoking abstinence, and decrease referral of individuals ineligible or unlikely to adhere.