# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

Notes. *One study reported both qualitative and quantitative data.

Abbreviations. KQ=key question.

## OVERVIEW OF INCLUDED STUDIES

Our search identified 129 potentially relevant articles after deduplication and title and abstract screening. Of these, 39 primary studies met eligibility criteria. Of the included studies, 30 provided only quantitative outcomes, 8 provided only qualitative outcomes, and 1 study provided quantitative and qualitative outcomes.^18^

Characteristics of included quantitative studies are shown in Table 1. A pre-post design was most used (15/39), though 12 studies (31%) were RCTs. Two-thirds (26/39) used patient-facing tools, typically web or print based. Studies ranged in follow-up duration from 1 day to 14 months and included population sizes from 15 to over 19,000. Most studies had a follow-up of ≤ 6 months and used a variety of delivery methods. In addition to differences in design, intervention of interest, and follow-up period, studies also varied in analytic methodology and comparison condition. Comparators differed based on whether the study aim was to identify the optimal intervention delivery mode or to examine whether a decision aid was superior to another decision aid, to an educational tool, or to usual care. Additionally, we conducted a narrative synthesis of just the RCTs which follows the summarization of all included studies. We identified 22 ongoing or recently funded studies (see Appendix).

Two quantitative studies evaluating effectiveness^19,20^ and 2 qualitative studies assessing barriers and facilitators were in Veteran populations.^21,22^ Of the quantitative studies, 1 was an RCT that compared the LCSDec tool to an attention control intervention.^19^ The second quantitative study used a cohort design and followed a group of individuals who received an LCS brochure in conjunction with an in-person or telephone visit with a health care provider.^20^ Neither study evaluated the tool currently available from the VA Lung Cancer Program Office and mentioned in a VA guidance statement (https://www.prevention.va.gov/preventing_diseases/screening_for_lung_cancer.asp). One additional study evaluated the tool developed for the VA LCS demonstration project and compared it to shouldiscreen.com, the most commonly referenced SDM tool among the included studies.^23^

The quantitative studies varied in design, intervention of interest, comparator, and analytic methodology. Thus, we provide a narrative synthesis rather than quantitative analysis. Study purpose also varied, with investigative intention including comparison of intervention delivery mode; different decision aids; decision aid to educational tool; and decision aid or educational tool to usual care. This heterogeneity across so many domains made study grouping challenging. To facilitate narrative synthesis, we grouped available studies by whether they examined a health care professional-facing tool (k = 9) or patient-facing tool (k = 26). Within the studies assessing health care-professional facing SDM tools, we further subdivided these into studies evaluating a tool for clinician (eg, physician or nurse practitioner) use or studies evaluating tools for LCS navigator use (eg, study coordinator or SDM program navigator). Two studies did not fit into either large category; these are discussed in an “other” group. Studies with a patient-facing tool were subdivided into those used during or prior to a SDM clinic visit or those meant to generate a SDM visit.

Assignment of the intervention to either the decision aid or educational tool category (or whether they met criteria for shared/informed medical decision-making or would meet CMS criteria) was not always feasible, as not all authors provided a copy or access to the tested intervention. As such, we relied on author report of the tool as a decision aid or educational tool; we refer throughout the text to both as SDM tools. Similarly, we did not assess the accuracy of information provided in any of the SDM tools or concordance with current US-based national LCS recommendations.

We first describe the SDM tools or communication approaches compared with usual care, to assess SDM overall. Next, we describe results for effectiveness and comparative effectiveness RCTs. In the subsequent sections, we describe results grouped by type of intervention, as described above.

Table 1 Characteristics of Included Quantitative Studies

| Risk of Bias | | | Total
| Low | Moderate/Some Concerns | High
Study Design
Cohort | 0 | 3 | 1 | 4
Pre/Post | 5 | 9 | 0 | 14
RCT | 3 | 6 | 3 | 12
CCT | 0 | 1 | 0 | 1
Health Care Professional- or Patient-Facing
Health care professional-facing | 1 | 8 | 0 | 9
Patient-facing | 7 | 10 | 3 | 20
Other | 0 | 1 | 1 | 2
Follow–Up
Same day (0) | 2 | 7 | 1 | 10
1–6 months | 2 | 6 | 3 | 11
≥ 6 months | 4 | 6 | 0 | 10
Intervention Delivery Method *
Web (static) | 3 | 7 | 1 | 11
Web (video) | 3 | 6 | 0 | 9
Person | 1 | 8 | 2 | 11
Print | 3 | 8 | 3 | 14
SDM not specified | 0 | 2 | 1 | 3
Decision Aid
Author described as decision aid | 6 | 14 | 1 | 21
Not described as decision aid | 2 | 5 | 3 | 10
International Patient Decision Aid Standards (Among Studies Described as a Decision Aid)
Author described decision aid as meeting IPDAS standards | 5 | 7 | 1 | 13
Not described as meeting IPDAS standards | 1 | 7 | | 8
Trial Population (N)
10-100 | 5 | 9 | 0 | 14
101-500 | 2 | 5 | 2 | 9
501-2,500 | 1 | 4 | 1 | 6
≥ 2,500 | 0 | 1 | 1 | 2

Notes.

* Groups are not mutually exclusive.

Abbreviations. CCT=controlled clinical trial; IPDAS=International Patient Decision Aids Standards; RCT=randomized controlled trial; SDM=shared decision-making.

## KEY QUESTION 1 TOOLS AND STRATEGIES REPORTED

Table 2 provides a list and brief description with author name and citation of reported tools and strategies characterized by whether they were print/brochure, video, or website/electronic viewing. As noted earlier, authors frequently did not provide sufficient information to determine if the studied tools met Medicare requirements of using an evidence-based patient decision aid or whether the tools met or were developed in accordance with International Patient Decision Aid Standards (IPDAS) criteria for a decision aid.^6,24^ Among the 21 tools, 13 (62%) were described by authors as decision aids. The most studied tool was a decision aid available in English, Spanish, and Chinese at (www.shouldiscreen.com) first deployed in 2015 after feedback from potential users and health risk communication experts. The tool was updated to include 2021 USPSTF recommendations and content.

Table 2 Tools or Approaches Identified for Use in Shared Decision-Making

Tool or Approach Identified | Publications
Brochures and Printed Materials
2-page brochure from a lung cancer advocacy group | Volk, 2020^*^
Brochure about LCS with a tear-off feature to promote contact with their health care provider; coupled with in-depth messaging from quit line staff via telephone | Sharma, 2018
Mailed letter, facemask, LCS brochure; second mailing including Native American traditional medicine and story book about traditional tobacco | Robichaux, 2023
Option Grid 1-page printed document in FAQ format | Ito Fukunaga, 2022^*^; Han, 2019^*^
Videos
“Lung Cancer Screening: Is It Right for Me?”; (6- and 9.5-minute versions) | Volk, 2014^*^; Volk, 2020^*^; Hoffman, 2018^*^
A YouTube educational video on lung cancer screening (runtime not reported) | Strong, 2020
6-minute Supporting Appropriate Implementation of Lung Cancer Screening (SAILS) decision aid video | Reuland, 2018^*^
A 4.5-minute video decision aid including incidental findings | Clark, 2022^*^
6-minute video slideshow | Mazzone, 2017^*^
Websites or Electronic Viewing/Interaction
www.shouldiscreen.com; 5-15 minutes as electronic or print versions; available in English, Spanish, Chinese | Webster, 2023^*^; Lau, 2015^*^; Lau, 2021^*^; Crothers, 2016^*^; Mazzone, 2017^*^; Tanner, 2019^*^; Sferra, 2021^*^
Decision Counselling Program (online software application) | Bittner Fagan, 2023^*^; Bittner Fagan, 2020^*^; DiCarlo, 2022^*^
Option Grids | DiCarlo, 2022^*^; Sferra, 2021^*^
Brief educational narrative coupled with an exercise on decisional regret administered through a website | Studts, 2020
LungTalk (computer-tailored decision support tool, with messages tailored by smoking status) | Carter-Harris, 2020^*^
Generic information sheet online about lung cancer screening developed by the American Cancer Society | Carter-Harris, 2020^*^
LungCare (administered on a touch tablet in waiting room prior to primary care appointment) | Walsh, 2023^*^
LCSDecTool is an online tool intended to be used independently before a clinic visit | Schapira, 2023^*^
Web-based 10-page guide that provided general information on cancer prevention and screening guidelines | Schapira, 2023^*^
Other Miscellaneous
Education on screening via 1 of 3 formats: numbers, numbers plus icons, or numbers plus slides | Fraenkel, 2016
Patients attend a group education class led by specialists before a personal shared decision-making visit is scheduled | Sakoda, 2020
Two educational sessions, one led by a radiologist focused on LCS process, and a second led by mental health clinician focused on smoking cessation | Flores, 2021
Patient navigation program: navigators discussed screening and helped patients through the health care system | Percac-Lima, 2018
PLCOm2012 risk calculator | Han, 2019^*^; Tanner, 2019^*^
Clinician-facing EHR prompts and an EHR-integrated SDM tool | Kukhareva, 2023^*^

Notes.

* Author referred to tool as “decision aid.”

Abbreviations. EHR=electronic health record; FAQ=frequently asked questions; LCS=lung cancer screening; LCSDecTool=lung cancer screening decision tool; SDM=shared decision-making.

## KEY QUESTION 2 EVIDENCE STRATIFIED BY TYPE OF INTERVENTION

We organized and present evidence by whether the tool was a health care provider-facing tool (eg, used in clinic and meant to guide the discussion) or a patient-facing tool or material (eg, meant to inform the patient either prior to or during the visit but not guide discussion). Within the health care provider-facing tools, we stratified by whether the tool was meant to be used by a clinician or LCS navigator. Within the patient-facing tools, we stratified by whether the tool was meant to be used prior to, or during, a scheduled SDM visit or if the tool was meant to generate a SDM visit. Studies that investigated tools or settings that did not fit into the previously mentioned categories were summarized separately. Of note, no studies reported on the following outcomes: receipt of additional tests/procedures for identified findings; participant need for additional information; smoking behaviors; and resource allocations/usage (eg, primary clinician time, additional clinical staff time, patient time, medical media support, IT support, cost, or cost effectiveness.

### Health Care Professional-Facing Tools or Materials

We identified 9 studies that evaluated tools or materials that were used in conjunction with a conversation with a health care professional and categorized as “health care professional-facing tools or materials.”^18,20,25–31^ We further categorized these studies into 2 groups: tools used by a clinician (eg, physician or nurse practitioner) and tools used by lung cancer screening coordinators or patient navigators. Tools described below were used during an in-person or phone encounter with a health care professional. These tools are all described as “health care professional-facing,” though it is possible that the patients were also viewing the tools during in-person visits. This was not clearly reported in most studies. Therefore, we referred to these as “health care professional-facing” tools throughout for consistency.

#### Tools for Clinician Use During SDM Clinic Visit to Help Guide Discussion With The Patient

Five studies used an intervention that involved a conversation with a clinician (eg, physician or nurse practitioner) and the utilization of a decision aid. Two pre-post studies used the same single-page paper-based decision aid designed to guide the conversation.^18,28^ One RCT and 1 cohort study utilized shouldiscreen.com in various ways. The RCT compared shouldiscreen.com to Option Grids,^31^ and the cohort study evaluated an in-person versus a phone SDM visit, using a paper decision aid (not provided), a risk assessment with the Prostate, Lung, Colorectal and Ovarian (PLCO) calculator, and shouldiscreen.com.^20^ One controlled clinical trial evaluated an integrated clinician-facing electronic medical record (EMR) template, comparing data before and after implementation.^29^

Most studies were rated moderate/some concerns RoB,^20,28,29,31^ and only 1 was rated as low RoB.^18^ Three studies reported on receipt of LCS,^17,19,26^ 3 reported on decisional conflict/regret,^19,25,28^ 2 reported on patient knowledge,^25,28^ 1 reported on quality of communication,^28^ and 1 reported on satisfaction with decision.^19^ No studies reported on concordance of decision, receipt of additional tests or procedures, patient need for additional information, smoking behaviors, resource allocation/usage, cost, or adherence to the screening program. Outcomes reported and the direction of effect are provided in Table 3. Certainty of evidence ratings for selected outcomes are reported in Table 4. Detailed study characteristics and results can be found in the Appendix.

##### Receipt of Lung Cancer Screening

Three studies evaluated the effect of SDM on receipt of LCS. One pragmatic clinical trial (N = 2,116) investigated a SDM tool integrated into the electronic medical record (EMR). This study compared a 12-month pre-implementation period to a 9-month post-implementation period and concluded that the integrated EMR tool significantly increased the proportion of eligible patients that received LCS (OR = 4.7, 95% CI [3.1, 7.1]) (moderate CoE, Table 4). This trial noted similar effects regardless of patient sex (female: OR = 4.8, 95% CI [2.4, 9.5]; male: OR = 4.6; 95% CI [2.7, 7.8]). Authors planned to investigate the effect in different race/ethnicity groups but did not provide information.^29^

One cohort study compared an in-person SDM visit to a telephone SDM visit, finding little to no difference between the modes of SDM delivery in regards to receipt of lung cancer screening at 1-month follow-up (very low CoE, Table 4).^20^ The third study was a pre-post study that reported 100% of the participants received screening after engaging in SDM with a printed “FAQ” document.^18^

##### Decisional Conflict/Regret

Three studies, all rated moderate or “some concerns” RoB, evaluated decisional conflict or regret. One RCT concluded that SDM using Option Grids led to significantly less decisional conflict/regret compared with SDM using shouldiscreen.com, as measured with the Ottawa Decision Regret scale (range 0-100 with higher scores indicating more regret) at 6 months (low CoE, Table 4).^31^ One cohort study compared an in-person SDM visit to a telephone SDM visit, finding little to no difference between the modes of SDM delivery in decisional conflict or regret as measured by the Decisional Conflict Scale at 1-month follow-up (range 0-20 with higher scores indicating greater conflict).^20^ The third study was a pre-post study that concluded decisional conflict or regret was significantly reduced after viewing a 1-page printed FAQ document.^28^

##### Quality of Communication

One RCT rated some concerns RoB concluded that there was no significant effect between Option Grids and shouldiscreen.com when measuring quality of communication with CollaboRATE at 6-month follow-up (mean scores of 97.4% vs 98.6%, respectively) (low CoE, Table 4).^31^

##### Satisfaction with Decision

One cohort study rated moderate RoB reported that there was no significant difference in satisfaction with decision between in-person (26.7 ± 2.8) versus telephone (24.6 ± 5.6) SDM visits, as measured with the Satisfaction With Decisions scale (range 0-30 with higher scores indicating greater satisfaction) at 1-month follow-up.^20^

##### Knowledge

Two studies evaluated knowledge of LCS benefits and harms. One RCT rated some concerns RoB concluded that there was no significant effect between Option Grids and shouldiscreen.com when measuring knowledge with an author-developed scale at 6-month follow-up (mean scores of 67.4% vs 62.4% correctly answered questions in each group, respectively).^31^ The second pre-post study rated moderate RoB only provided knowledge scores collected immediately post intervention.^28^

Table 3 Outcomes Reported and Direction of Effect for Tools for Clinician Use

Author, Year; Sample Size; Intervention | Outcomes With Certainty of Evidence Assessments | | | | | | Outcomes Without Certainty of Evidence Assessments
Author, Year; Sample Size; Intervention | Adherence | Receipt of Lung Cancer Screening | Concordance of Decision | Decisional Conflict/Regret | Distress/Anxiety | Overall Quality of Communication | Receipt of Additional Tests/Procedures | Satisfaction with Decision | Participant Need for Additional Information | Knowledge
RCT
Sferra, 2021^31^; N = 237; SDM discussion utilizing Option Grids vs shouldiscreen.com | - | - | - | ↓ | - | ↔ | - | - | - | ↔
Controlled Clinical Trial
Kukhareva, 2023^29^; N = 2116; EHR prompts and integrated SDM tool (pre-post implementation of tool) | - | ↑ | - | - | - | - | - | - | - | -
Cohort
Tanner, 2019^20^; N = 137; In-person vs telephone SDM visit with printed materials, PLCOm2012 calculator, and shouldiscreen.com | - | ↔ | - | ↔ | - | - | - | ↔ | - | -
Pre-Post
Han, 2019^18^; N = 60; Option Grid 1-page FAQ and PLCOm2012 calculator | - | ↔ | - | - | - | - | - | - | - | -
Ito Fukunaga, 2022^28^; N =23; Option Grid 1-page FAQ | - | - | - | ↓ | - | - | - | - | - | NA^*^

Notes.

* Knowledge scores were only reported post-intervention.

↑ mean scores increased after receiving intervention, in favor of intervention

↔ no difference between arms after receiving intervention

↓ mean scores decreased after receiving intervention, in favor of intervention

Abbreviations. EHR=Electronic health record; FAQ=frequently asked questions; PLCO=Prostate, Lung, Colorectal and Ovarian; SDM=shared decision-making.

Table 4 Certainty of Evidence for Clinician-Facing SDM Tools or Approaches

Outcome | Measurement Tool Follow-up | Total № of Participants (Studies) | Findings | Certainty | Importance
Receipt of Lung Cancer Screening | % receiving screening in 12-mo pre-intervention phase vs 9-months post intervention phase | N = 2116; (1 CCT)^29^ | OR = 4.7, 95% CI [3.1, 7.1], p < 0.001 | ⊕⊕⊕◯; Moderate^a,b^ | An EMR-integrated SDM tool probably results in a greater % receiving lung cancer screening, compared with no EMR integrated tool.
Receipt of Lung Cancer Screening | % receiving screening at 1-3 months | N = 197; (1 cohort) ^20^ | One cohort study reported 88.4% and 88.2% in the inperson and telephone groups (respectively) | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of in-person compared with telephone SDM on receipt of lung cancer screening.
Decisional Conflict or Regret | Ottawa Decision Regret Scale; 6 months | N = 237; (1 RCT)^31^ | Mean scores 6.0 (Option Grids) vs. 10.2 (shouldiscreen.com), p = 0.02 | ⊕⊕◯◯; Low^a,c^ | Option Grids may result in less decisional conflict or regret compared with shouldiscreen.com.
Quality of Communication | CollaboRATE; 6 months | N = 237; (1 RCT)^31^ | Mean scores 97.4% (Option Grids) vs. 98.6% (shouldiscreen.com), p = 0.6 | ⊕⊕◯◯; Low^a,c^ | There may be little to no difference in quality of communication in SDM using Option Grids compared with shouldiscreen.com.

Notes. GRADE Working Group grades of evidence:

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Rated down 1 level for study limitations (rated some concerns or moderate risk of bias).

b Rated up 1 level for magnitude of effect.

c Rated down 1 level for imprecision (optimal information size not met, sample size <400).

Abbreviations. RCT=randomized controlled trial; SDM=shared decision-making.

#### Tools for LCS navigator Use to Help Guide SDM Discussion

Four included studies evaluated SDM tools intended for the use of LCS navigators: decision counselors,^25,26^ care coordinators,^27^ and patient navigators.^30^ SDM tools varied across studies: 3 studies used the Decision Counseling Program in some capacity,^25–27^, 1 used Option Grid,^27^ and another used a patient navigation program to introduce SDM to participants.^30^ Two studies were RCTs,^27,30^ 1 was a cohort study,^26^ and 1 was a pre-post design.^25^

All studies were rated moderate or some concerns RoB. All 4 studies reported receipt of LCS,^25–27,30^ 1 study reported decisional conflict/regret,^25^ and 1 study reported receipt of additional tests/procedures.^30^ No studies reported the effect of tools for LCS navigator SDM on adherence, concordance of decision, distress/anxiety, overall quality of communication, satisfaction with decision, participant need for additional information, knowledge, smoking behaviors, resource allocation/usage, or costs. Outcomes reported and the direction of effect are provided in Table 5. Certainty of evidence ratings for selected outcomes are reported in Table 6. Detailed study characteristics and results can be found in the Appendix.

##### Receipt of Lung Cancer Screening

Two RCT studies,^27,30^ 1 cohort study,^26^ and 1 pre-post study assessed the number of individuals that completed at least 1 LCS appointment.^25^ Both RCTs found a statistically significant difference for receipt of lung cancer screening favoring the intervention arms that included care coordinators and patient navigators (low CoE, Table 6). LCS rates were low in both studies. The trial that compared outreach with a mailed informational material, including a print decision aid (Option Grid), with a review guided by a care coordinator with (OC-DC) and without (OC) an online support application (Decision Counseling Program) versus usual care (UC) found that 5.5% of participants in the combined 2 SDM groups (OC + OC-DC) completed LCS, compared with 1.8% of those receiving usual care (UC) (p = 0.001) at 280 days. Of note, LCS did not differ between those receiving online support (OC-DC) and those who did not (OC) (7.0% and 4.0% respectively, p = 0.12).^27^ Authors did not evaluate the statistical significance separately of either OC-DC or OC versus UC. The other trial evaluated a patient navigation program to promote LCS and provide SDM compared with usual care among low socioeconomic people who currently smoke. Authors found that 23.5% of the intervention arm completed LCS, compared with 8.6% of usual care (p < 0.001)^30^ Results did not differ by race, sex, or age category.

The cohort study started with a pool of 1,359 potentially eligible participants, of which 80 met eligibility criteria and agreed to be in the study. Of the included 80 participants, 64 used the Decision Counseling Program, while 16 were not reached and did not receive the intervention. The study found that 45.3% (29/64) of those that completed the counseling session also completed lung cancer screening, compared with 0% (0/16) in those that did not use the SDM tool (p = 0.0003).^26^

Finally, the pre-post study enrolled 28 participants from a pool of 829 eligible participants, of which 20 received the intervention. This study found that 45% (9/20) of participants that completed the intervention received LCS.^25^

##### Decisional Conflict/Regret

One pre-post study evaluated decisional conflict using a 16-item 5-point Likert decisional conflict scale to compare pre and post the intervention. Only 11 of the 20 participants who received the intervention completed the follow-up assessment. Among those that completed the follow-up assessment, there was no statistically significant difference in decisional conflict compared with their pre-intervention assessment (very low CoE, Table 6). The study also analyzed people who currently and formerly smoked separately. While there was still not statistically significant difference in decisional conflict, sample sizes were small.^25^

##### Receipt of Additional Tests/Procedures

One RCT reported that following LCS additional tests and procedures (including additional imaging, biopsies, surgery, and chemotherapy) were “similar in both” the navigated and usual care groups.^30^

Table 5 Outcomes Reported and Direction of Effect for Tools for LCS Navigator Use

Author, Year; Sample Size; Intervention | Outcomes With Certainty of Evidence Assessments | | | | | | Outcomes Without Certainty of Evidence Assessments
Author, Year; Sample Size; Intervention | Adherence | Receipt of Lung Cancer Screening | Concordance of Decision | Decisional Conflict/Regret | Distress/Anxiety | Overall Quality of Communication | Receipt of Additional Tests/Procedures | Satisfaction With Decision | Participant Need for Additional Information | Knowledge
RCT
DiCarlo, 2022^27^; N = 2376; Reviewed mailed material including printed Option Grid decision aid with care coordinator, with or without additional review of Decision; Counseling Program vs usual care | - | ↑ | - | - | - | - | - | - | - | -
DiCarlo, 2022^27^; N = 628; Reviewed mailed material including printed Option Grid decision aid with care coordinator, with vs without additional review of Decision; Counseling Program | - | ↔ | - | - | - | - | - | - | - | -
Percac-Lima, 2018^30^; N = 1200; Patient navigator program plus SDM vs usual care | - | ↑ | - | - | - | - | ↔ | - | - | -
Cohort
Bittner Fagan, 2023^26^; N = 80; Phone call guiding patient through Decision; Counseling Program, followed by visit with PCP or LCS program | - | ↑ | - | - | - | - | - | - | - | -
Pre-Post
Bittner Fagan, 2020^25^; N = 28; Phone call with decision counselor who guided patient using Decision Counseling Program | - | 45% | - | ↔ | - | - | - | - | - | -

↑ mean scores increased after receiving intervention, in favor of intervention

↔ no difference between arms after receiving intervention

↓ mean scores decreased after receiving intervention, in favor of intervention

Abbreviations. LCS=lung cancer screening; PCP=primary care provider; SDM=shared decision-making.

Table 6 Certainty of Evidence for LCS Navigator-Facing SDM Tools or Approaches

Outcome | Measurement Tool Follow-Up | Total № of Participants (Studies) | Findings | Certainty | Importance
Receipt of Lung Cancer Screening | % receiving screening; 280 days – 1 year | N = 3,547; (2 RCTs)^27,30^ | 127/999 (12.7%) SDM tools plus care coordination vs 100/2548 (3.9%) usual care | ⊕⊕◯◯; Low^a,b^ | SDM tools combined with care coordination may result in increased receipt of lung cancer screening compared with usual care.
Decisional Conflict or Regret | Decisional Conflict Scale; 30 days | N = 28; (1 pre-post)^25^ | Mean difference = −0.57 | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of SDM tools on decisional conflict/regret.

Notes. GRADE Working Group grades of evidence:

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Rated down 1 level for study limitations (studies rated some concerns RoB).

b Rated down 1 level for imprecision (event rate too low).

c Rated down 2 levels for imprecision (OIS not met, sample size <150).

Abbreviations. RCT=randomized controlled trial; SDM=shared decision-making.

### Patient-Facing Tools or Materials

We identified 20 studies that evaluated tools or materials that were developed with the intention that the patient or participant would view the item either prior to or during the SDM clinic visit. We categorized these studies into 2 groups: 1 consisting of tools used prior to or during the visit, and 1 consisting of tools that were meant to inform the patient or participant and potentially generate an SDM visit but no requirement to interact with a health care professional.

#### Tools for Patients’ Use During or Prior to SDM Clinic Visit

Five studies incorporated materials provided to patients to review during or before a scheduled visit with a clinician to help guide the discussion or inform the patients about LCS prior to discussing options with their clinician.^19,32–35^

Tools varied across the studies, with 3 making use of web or video content and the remaining 2 studies using counseling by specialists associated with lung cancer screening (Table 7). Two studies were RCTs^19,35^ and the remaining 3 were a pre-post design.^32–34^

The following outcomes were not reported in any of the included studies that included an intervention aimed at patients to use before or during a SDM visit: adherence, satisfaction with decision, concordance of decision, receipt of additional tests/procedures, participant need for additional information, smoking behaviors, resource allocations/usage, or costs. Outcomes reported and the direction of effect are provided in Table 7. Certainty of evidence ratings for selected outcomes are reported in Table 8. Detailed study characteristics and results can be found in the Appendix.

##### Receipt of Lung Cancer Screening

Two RCTs^19,35^ and 1 pre-post study^33^ captured the number of individuals that completed a first LCS appointment, with all 3 finding that exposure to SDM increased uptake of LCS. The 2 RCTs found a difference in uptake between the intervention and control arms, with those in the intervention arm having greater lung cancer screening. One cluster-randomized trial compared those randomized to SDM using the tablet-based LungCare tool with those receiving usual care.^35^Among the subset of patients randomized to LungCare who completed baseline and follow-up surveys (32/41), 32% completed a LCS visit versus 13% (p = 0.01) in the usual care control arm (very low CoE, Table 8). The second trial compared a web-based LCSDecTool with a web-based attention control guide that included general information on cancer prevention and the USPSTF LCS screening guidelines. Authors reported an 18.8 percentage point difference (95% CI [4.4, 33.2]; p = 0.02) between the intervention (31 of 69, 44.9%) and control (18 of 71, 25.4%) arm at 9 months (low CoE, Table 8).^19^ The 1 pre-post study used EHR records to assess uptake of LCS after an in-person SDM visit that included a review of patient eligibility criteria, presentation of a 6-min narrated video slide show describing the benefits and harms of LCS, the use of a decision aid (shouldiscreen.com), and an opportunity for patients to ask questions throughout the visit. Authors reported 94.6% of individuals attending and completing the SDM visit completed an LCS visit.^33^

##### Decisional Regret

The RCT by Schapira, 2023 reported decisional regret as an outcome, finding no difference between the intervention and control groups over time (low CoE, Table 8).^19^ Study authors used the Decisional Conflict Scale (DCS; a 16-item scale with 5 subscales, with scores ranging from 0 to 100; a score lower than 25 is associated with implementing decisions and greater than 37.5 with decision delay or feeling unsure about implementation) to measure decisional conflict immediately and 1 and 3 months post intervention. Immediately after the intervention, those in the intervention arm had a lower DCS mean score 22.2 (95% CI [18.3, 26.0]) score than those in the control arm 31.1 (26.1, 36.0; p = 0.004). However, by the first and third month, between-group differences were no longer statistically significant (p = 0.18 and 0.33, respectively). Decisional regret was also measured using a scale developed by Brehaut et al immediately after intervention, 1-month, and 3-months follow up.^36^ There was no between-group difference at any of the 3 time points. Authors analyzed decisional conflict and regret separately for those identifying as African American or Black. They compared those that identified as African American or Black in the intervention arm to those identifying as African American or Black in the control arm and at 3 months found no between-group difference in decisional conflict.

##### Distress/Anxiety

One RCT^19^ and 1 pre-post study^32^ reported distress and anxiety after completion of the SDM visit. Schapira, 2023 used the State Trait Anxiety Inventory (range 20-80 with higher scores indicating greater distress) to measure anxiety among those exposed to the LCSDecTool compared with controls, immediately after the SDM visit, 1 month, and 3 months. At all 3 time points the level of anxiety did not differ between the LCSDecTool and control groups (p = 0.86, 0.30, 0.74, respectively) (Low CoE, Table 8). The pre-post study by Flores, 2021 found a reduction (p = 0.03) in distress/anxiety, measured with an author-developed question, after the study population had participated in an educational session on LCS.^32^

##### Quality of Communication

Two pre-post studies^32,33^ measured various aspects of what we categorized as “quality of communication” among a subset of participants. Among those responding to the post survey, the majority (93% and 86.4%) described the SDM tool positively, with those in the Flores, 2021 study^32^ strongly agreeing or agreeing with: “Overall, I was satisfied with the educational sessions” and 57 of the 66 respondents in the Mazzone et al study^33^ providing positive feedback such as: “good presentation helped me to make an informed choice,” “Excellent!,” or “No unnecessary pressure-honest, highly intelligent, and sensitive to needs of my whole life” (Low CoE, Table 8).

##### Knowledge

Four of the 5 studies reported a measure of knowledge, with all 4 reporting an increase in knowledge after viewing of the SDM tool.^19,33–35^ Each study created its own tool to assess knowledge and assessed knowledge at varying time points, from immediately^34^ to 3 months^19^ after use of the SDM tool. In the RCT by Schapira, 2023, improvement in LCS knowledge score (range 0-12 with higher scores indicating greater knowledge) was higher immediately after intervention (7.0 vs 4.9, mean difference = 2.0; 95% CI [1.2, 2.8]; p < 0.001) and remained higher at 1- and 3-months follow-up. In the RCT by Walsh, 2023,^35^ knowledge scores based on the mean total number of correct answers out of 10 were greater in the intervention group (6.5 [range 3-9] vs 5.5 [range 3-8], p < 0.01).

Table 7 Outcomes Reported and Direction of Effect for Patient-Facing Tools for Patient Use During or Prior to SDM Clinic Visit Results

Author, Year; Sample Size; Intervention | Outcomes With Certainty of Evidence Assessments | | | | | | Outcomes Without Certainty of Evidence Assessments
Author, Year; Sample Size; Intervention | Adherence | Receipt of Lung Cancer Screening | Concordance of Decision | Decisional Conflict/Regret | Distress/Anxiety | Overall Quality of Communication | Receipt of Additional Tests/Procedures | Satisfaction With Decision | Participant Need for Additional Information | Knowledge
RCT
Walsh, 2023 ^35^; N = 66; LungCare delivered on tablet in waiting room prior to visit | - | ↑ | - | - | - | - | - | - | - | ↑
Schapira, 2023 ^19^; N = 140; Web-based Lung Cancer Screening Decision Tool (LCSDecTool) used independently before clinic visit versus attention control | - | ↑ | - | ↔ | ↔ | - | - | - | - | ↑
Pre-Post
Flores, 2021 ^32^; N = 15; Two 30-minute educational sessions led by a radiologist and mental health clinician | - | - | - | - | ↓ | 93%; (satisfied with tool) | - | - | - | -
Sakoda, 2020 ^34^; N = 680; Group education class led by a specialist prior to a clinic visit | - | - | - | - | - | - | - | - | - | ↑
Mazzone, 2017 ^33^; N = 423; Counseling and a 6 min video (shouldiscreen.com) | - | 94.6%; screened | - | - | - | 86.4%; (positive comments) | - | - | - | ↑ *

Notes.

* Knowledge scores were reported for knowledge domains: age eligibility, smoking eligibility, benefits of LCS, and harms of LCS.

↑ mean scores increased after receiving intervention, in favor of intervention

↔ no difference between arms after receiving intervention

↓ mean scores decreased after receiving intervention, in favor of intervention

Table 8 Certainty of Evidence for Tools for Patient Use During or Prior to SDM Visit

Outcome | Measurement Tool; Follow-up | Total № of Participants (Studies) | Findings | Certainty | Importance
Receipt of Lung Cancer Screening | % receiving screening; 2 months | N = 66; (1 RCT)^35^ | 32% LungCare vs 13% usual care | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of LungCare on receipt of lung cancer screening compared with usual care.
Receipt of Lung Cancer Screening | % receiving screening; 6 months | N = 140; (1 RCT)^19^ | 18 percentage point difference between LungCare and usual care | ⊕⊕◯◯; Low^b^ | LCSDecTool may result in increased lung cancer screening compared with usual care (attention control).
Quality of Communication | Author-developed; Same day –1 month | N = 438; (2 pre-post)^32,33^ | 93% and 86.4% described SDM tool positively | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of SDM tools on quality of communication.
Decisional Conflict/Regret | Decisional Conflict Scale; 3 months | N = 140; (1 RCT)^19^ | LungCare 24.2 (20.8, 27.6) vs usual care 27.5 (23.3, 31.7) with a between group difference of −2.9 (−8.9, 3.0), p = 0.33 | ⊕⊕◯◯; Low^b^ | LCSDecTool may result in little to no difference in distress/anxiety compared with usual care (attention control).
Distress/Anxiety | State Trait Anxiety Index; 3 months | N = 140; (1 RCT)^19^ | No statistically significant difference between LungCare and usual care | ⊕⊕◯◯; Low^b^ | LCSDecTool may result in little to no difference in distress/anxiety compared with usual care (attention control).

Notes. GRADE Working Group grades of evidence:

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Rated down 1 level for study limitations (study rated some concerns/moderate RoB).

b Rated down 2 levels for imprecision (OIS not met, sample size <150).

c Rated down 1 level for indirectness (study used unvalidated measurement tool).

Abbreviations. LCSDecTool=lung cancer screening decision tool; RCT=randomized controlled trial.

#### Tools or Materials for Patient Education and to Potentially Generate SDM Visits

Fifteen studies included materials or tools that were provided to patients at risk for lung cancer to inform them about lung cancer screening but without a conversation with a clinician or any type of scheduled clinic visit within a health care system.^23,37–39,40–42,43–47,48–50^

Authors utilized diverse tools. Four studies^23,37–39^ utilized a version of shouldiscreen.com, 3 studies^40–42^ used a decision aid video called “Lung Cancer Screening: Is It Right For Me?”, 5 studies^43–47^ used a variety of video and/or web based media, and the remaining 3 studies^48#x2013;50^ used printed materials (Table 9). Seven studies were RCTs^37,41,45,46,48–50^ and 9 were pre-post studies.^23,38–40,42–44,47^ Of the 7 RCTs, 2 compared tools or materials with usual care and 5 compared 1 tool type or delivery mode with another.

The following outcomes were not reported in any of the included studies: adherence, smoking behaviors, resource allocation/usage, or costs. Outcomes reported and the direction of effect are provided in Table 10. Certainty of evidence ratings for selected outcomes are reported in Table 11. Detailed study characteristics and results can be found in the Appendix.

Table 9 Description of Interventions and Comparisons for Tools or Materials for Patient Education and to Potentially Generate SDM Visits

Author, Year (Design) | Intervention | Comparison
RCT
Carter-Harris, 2020 | LungTalk; a computer-tailored decision support tool, with messages tailored by smoking status | Viewed generic information sheet online about lung cancer screening developed by the American Cancer Society
Clark, 2022 | A 4.5-minute video decision aid including incidental findings information | Same video, without incidental findings information (4-min)
Fraenkel, 2016 | Education on screening via 3 different formats: Numbers | Numbers plus icons; numbers plus slides
Robichaux, 2023 | Mailed letter, facemask, LCS brochure; second mailing including Native American traditional medicine and story book about traditional tobacco | Mailed letter, facemask, LCS brochure
Sharma, 2018 | Brochure about LCS with a tear-off feature to promote contact with their health care provider; coupled with indepth messaging from quit line staff via telephone | Brochure about LCS with a tear-off feature to promote contact with their health care provider
Volk, 2020 | 9.5-minute narrated video “Lung Cancer Screening: Is It Right for Me?” | 2-page brochure from a lung cancer advocacy group
Webster 2023 | Provided with shouldiscreen.com website when contacting Quitline | Provided with shouldiscreen.com printed materials when contacting Quitline
Pre-Post
Crothers, 2016 | Review of shouldiscreen.com and printed pamphlet during focus groups | NA
Hoffman, 2018 | “Lung Cancer Screening: Is It Right for Me?” viewed online | NA
Lau, 2015 | Initial development of shouldiscreen.com | NA
Lau, 2021 | Provided with shouldiscreen.com website at community center | NA
Reuland, 2018 | 6-minute SAILS decision aid video | NA
Strong, 2020 | An educational video about lung cancer screening hosted on YouTube | NA
Studts, 2020 | Brief educational narrative coupled with an exercise on decisional regret administered through a website | NA
Volk, 2014 | 6-minute video “Lung Cancer Screening: Is It Right for Me?” | NA

##### Receipt of Lung Cancer Screening

Four RCTs reported participants who completed a LCS appointment.^37,41,48,49^ All reported no difference in receipt of LCS at 4-6 months between intervention and control arms. Volk, 2020 evaluated the video “Lung Cancer Screening: Is It Right for Me?” vs standard educational materials.^41^ “Lung Cancer Screening: Is It Right for Me?” video results in no difference in receipt of lung cancer screening compared with 2-page brochure from a lung cancer advocacy group (high CoE, Table 11). The other 3 RCTs evaluated different tools/modes of SDM delivery (very low CoE, Table 11).^37,48,49^ In their pre-post study, Reuland, 2018 reported that 10 out of 50 (20%) participants received LCS after viewing the SAILS Decision Aid.^47^

##### Concordance of Decision

Two pre-post studies reported on concordance, participants’ LCS preference, and eligibility.^38,39^ Lau, 2015 utilized the Ottawa Decision Support Framework and defined concordance as “participants who preferred to get screened and were also eligible for screening.” 14 participants (23.7%) were considered concordant pre-viewing of shouldiscreen.com and 35 participants (59.3%) were considered concordant post-viewing (p < 0.001; very low CoE, Table 11).^39^ Lau, 2021 determined concordance by the first question from the Decisional Conflict Scale: “Which option do you prefer? A) I prefer to screen; B) I prefer not to screen; C) Unsure.” There was a significant increase (+12 percentage points, p = 0.016) in participants’ concordance from pre-viewing of shouldiscreen.com (21%) to post-viewing (33%) (very low CoE, Table 11).^38^

##### Decisional Conflict/Regret

Two RCTs^37,41^ and 4 pre-post studies^38–40,44^ reported decisional conflict/regret. The 2 RCTs reported no difference in the measured decisional regret between the intervention and control arms, whereas the 4 pre-post studies reported an improvement after viewing of the intervention materials.^37–41,44^ Lau, 2015 and Lau, 2021 reported significant (p < 0.001) decreases in participants’ mean (SD) overall Decisional Conflict Scale score post-viewing of shouldiscreen.com (2015: 17.5 [11.4] vs 8.9 [9.7]; 2021: 46.3 [29.7] vs 15.1 [25.8], respectively).^38,39^ Hoffman, 2018 and Volk, 2020 reported the Values Clarity subscale of the Decisional Conflict Scale (range 0-100 with higher scores indicating less clarity about personal values).^40,41^ Hoffman, 2018 reported a mean score of 3.9 after watching the “Lung Cancer Screening: Is It Right for Me?” video. Volk, 2020 reported a significant (p < 0.001) mean difference of −14.1 (95% CI [−19.5, −8.7]) between “Lung Cancer Screening: Is It Right for Me?” video and standard education groups at 1-week follow-up, with participants in the video group showing lower decisional conflict than those in the standard education group.^41^ Additionally, Volk, 2020 reported a significant mean difference of −14.9 (95% CI [−20.1, −9.7]; p < 0.001) in the Decisional Conflict Scale-Informed subscale (range 0-100 with higher scores indicating feeling more uninformed) at 1 week between the video and standard education groups. “Lung Cancer Screening: Is It Right for Me?” video results in less decisional conflict/regret compared to a 2-page brochure from a lung cancer advocacy group at 1 week (high CoE, Table 11). A single pre-post study by Studts, 2020 utilized the modified low literacy DCS (DCS-LL) to help reduce the time burden for participants to complete the survey.^44^ Participants showed significantly lower mean decisional conflict scores after viewing a web-based educational narrative and completing an exercise on decisional regret (47.6 vs 18.3, p < 0.0001). Additionally, the authors found no significant differences in scores based on age, race/ethnicity, SES/education, or smoking status. Finally, a single RCT by Webster, 2023 used the Health Care Decisions scale to measure decisional conflict/regret.^51^ The authors reported mean (SD) scores for the shouldiscreen.com (2.9 [1.1]) and delayed intervention (2.7 [1.1]) at baseline and found no significant differences within or between groups at either 1 or 4 months (very low CoE, Table 11).^37^

##### Distress/Anxiety

A single RCT by Webster, 2023 asked participants if the materials made them feel “nervous or fearful about either LCS or about lung cancer.”^37^ They found that 47 (52.2%) participants in the shouldiscreen.com arm and 62 (54.4%) participants in the delayed intervention arm responded that they were “only a little,” “somewhat,” or “very much” nervous/fearful about LCS or lung cancer. There were no significant differences between groups. Shouldiscreen.com web may cause little to no difference compared to shouldiscreen.com print on distress/anxiety at 4 months (low CoE, Table 11).

##### Quality of Communication

Three RCTs^37,41,46^ and 1 pre-post study^42^ used author-developed questionnaires to measure participants’ perceived quality of communication. Webster, 2023 asked participants if “any parts of the materials were confusing or difficult to understand” and reported that 23 (25.6%) participants in the shouldiscreen.com group and 38 (33.3%) participants in the delayed intervention group answered “a little bit,” “moderately,” or “extremely.”^37^ Authors also asked participants if the materials helped prepare them to talk with their doctor about what matters most to them. They reported that only 9 (10%) participants in the intervention group and 5 (4.4%) participants in the delayed intervention group answered “not at all” to this question, though there were no significant group differences (very low CoE, Table 11). Authors state that while feedback for amount of information provided and preparedness was generally positive, 53.4% of participants reported “feeling at least ‘a little’ nervous or fearful about LCS or lung cancer.” Carter-Harris, 2020^46^ asked participants about their satisfaction with the LungTalk intervention or a non-tailored lung screening information sheet, as well their preparedness to talk to their clinician about LCS. They reported that satisfaction was significantly higher in the LungTalk group and that participants in both groups felt “prepared” or “very prepared” to discuss LCS with their clinician, though they did not report a p-value. However, there were no significant differences between groups on preparedness (p = 0.52). LungTalk may result in little to no difference in quality of communication compared to a non-tailored lung cancer screening information sheet at 1 week (low CoE, Table 11). In their pre-post study, Volk, 2014 asked participants for feedback on the video “Lung Cancer Screening: Is It Right for Me?” and found that “more than 94% of patients viewed the entire video, would recommend it to others, felt it held their interest, and wanted to view similar videos about health care decisions.”^42^ Volk, 2014 also reported 78.8% of participants stated that they would be more interested in screening after viewing.^42^ Finally, Volk, 2020 asked participants in the video decision aid group only for feedback and found that 198 (87.2%) participants thought that the video contained sufficient information to help them decide about LCS.^41^

##### Receipt of Additional Tests/Procedures

A single pre-post study by Reuland, 2018 reported a count of participants that received any additional tests or procedures after LCS. One (2%) patient had a category 4a LungRADS nodule and the 3-month follow-up scan showed resolution.^47^

##### Satisfaction with Decision

A single RCT by Webster, 2023 asked participants about their degree of satisfaction with their screening decision on a 5-point Likert scale at 1 and 4 months.^37^ Authors reported that in the web version of shouldiscreen.com, 96 (85.7%) participants at 1 month and 93 (86.1 %) participants at 4 months “strongly agreed” or “agreed” with their screening decision. In the printed version of shouldiscreen.com, 110 (93.2%) participants at 1 month and 99 (90.8%) participants at 4 months “strongly agreed” or “agreed” with their screening decision. Results were not statistically significant between groups.

##### Participant Need for Additional Information

One RCT^37^ and 2 pre-post studies^40,44^ reported participants’ need for additional information. In the RCT by Webster, 2023 comparing web and print versions of shouldiscreen.com, only 5 (5.6%) participants in the print group and 6 (5.3%) participants in the web group requested additional information, and there were no significant differences between groups.^37^ However, it was unclear exactly when participants requested additional information. Hoffman, 2018 asked how informed participants felt about lung cancer screening after watching the video “Lung Cancer Screening: Is It Right for Me?” and participants responded on a 10-point VAS scale (range 0-10 with higher scores indicating feeling more informed).^40^ Participants reported a mean (SD) VAS score of 8.7 (1.6). Finally, Studts, 2020 utilized the Informed subscale of modified version of the DCS-LL before and after viewing a web-based educational narrative and completing on exercise on decisional regret. Participants reported a pre-intervention mean (SD) score of 52.2 (30.5) and a post-intervention score of 16.9 (24.5).^44^ The difference of 35.3 between time points was significant (p < 0.0001).

##### Knowledge

5 RCTs^37,41,45,46,50^ and 7 pre-post studies^23,38–40,42,43,47^ reported knowledge of screening benefits and harms as an outcome. Two studies utilized the 12-item LCS measure.^40,43^ Hoffman, 2018 reported a statistically significant improvement (p < 0 .001) in the mean (SD) score of 3.9 (2.9) post-viewing of the video “Lung Cancer Screening: Is It Right for Me?”^40^ Similarly, Strong, 2020 showed statistically significant improvement in participants’ knowledge after watching a video on lung cancer screening (95% CI of the difference [−3.9, −1.9]; p = 0.00).^43^ Two studies utilized the Ottawa Decision Support Framework, or a measure derived from it, to measure change in knowledge after viewing shouldiscreen.com.^38,39^ Both studies found statistically significant (p < 0.001) improvements in knowledge. While Lau, 2015^39^ only reported the mean (SD) scores pre-intervention (7.5 [1.9]) and post-intervention (10.9 [2.2.]), Lau, 2021^38^ reported a 1.4-point improvement after viewing the video compared with before viewing. Volk, 2020 utilized a questionnaire developed by Lowenstein et al^52^ to measure the percentage of questions answered correctly at 6 months following use of a decision aid or standard education.^41^ Patients in the decision aid group answered 49.9% (95% CI [47.5, 52.3]) of questions correctly and the standard education group answered 40% (95% CI [37.6, 42.4]) of the questions correctly (p < 0.001). Carter-Harris, 2020 utilized the Knowledge of Lung and Lung Cancer Screening scale to measure change in knowledge after 1 week.^46^ The LungTalk intervention group had an improvement in mean scores of 2.3 points, while the general lung cancer information sheet group had an improvement of 1.1 points. Both changes were statistically significant (p < 0.01).

Five studies utilized an author-developed knowledge questionnaire.^23,42,45,47,50^ Clark, 2022 reported that changes in overall mean scores from pre- to post-intervention were similar in the group that watched a video that included information on incidental findings (2.8) versus the group that watched a video without incidental findings information (2.6 [SD NR]; p = 0.2).^45^ However, the participants that watched the video with the segment on incidental findings answered more questions correctly than those that watched the video without the incidental findings segment (94.8% vs 73.7%, p = 0.02). Reuland, 2018 found a significant increase (p < 0.001) of 2.8 points (95% CI [2.1, 3.6]) in participants’ mean knowledge scores before and after the viewing the SAILS decision aid video.^47^ Fraenkel, 2015 compared the presentation of information on LCS in 3 different formats: numbers only, numbers + icon array, and numbers + slides on LCS scans.^50^ Authors reported differences in knowledge (model-estimated mean [SE]) of 0.7 (0.01) in the numbers only arm, 1.2 (0.01) in the numbers + icon array arm, and 1.0 (0.01) in the numbers + slides arm. Only the comparison between the numbers only and the numbers + icon array were statistically different. Volk, 2014 stated that the mean (SD) percentage of correct answers on their knowledge questionnaire increased significantly (p < 0.01 for each question) from 25.5% (20.7) to 74.8% (20.2) after participants viewed the video “Lung Cancer Screening: Is It Right for Me?”^42^ Finally, Crothers, 2016 created a questionnaire with 20 true/false questions and reported the percentages of participants who answered each individual question correctly before and after a focus group and reading 2 decision aids.^23^ There was statistically significant improvement (p < 0.05) for 12 of the 20 questions. However, authors did not report any measure of mean overall knowledge.

Table 10 Outcomes Reported and Direction of Effect for Tools or Materials for Patient Education to Potentially Generate SDM Visit

Author, Year; Sample Size; Intervention | Outcomes With Certainty of Evidence Assessments | | | | | | Outcomes Without Certainty of Evidence Assessments
Author, Year; Sample Size; Intervention | Adherence | Receipt of Lung Cancer Screening | Concordance of Decision | Decisional Conflict/Regret | Distress/Anxiety | Overall Quality of Communication | Receipt of Additional Tests/Procedures | Satisfaction With Decision | Participant Need for Additional Information | Knowledge
RCT
Carter-Haris, 2020 ^46^; N = 60; LungTalk vs generic info sheet on lung cancer screening from the ACS | - | - | - | - | - | 73% very satisfied (intervention), 28% very satisfied (comparator) | - | - | - | ↑
Clark, 2022 ^45^; N = 348; Video decision aid with incidental findings segment vs video decision aid w/o incidental findings segment | - | - | - | - | - | - | - | - | - | ↑
Fraenkel, 2015 ^50^; N = 253; Education interface on screening via numbers only vs numbers + icons, or numbers + slides | - | - | - | - | - | - | - | - | - | ↑
Robichaux, 2023 ^48^; N = 469; Mailed letter, face mask, LCS brochure, & story about Native American traditional medicine vs LCS brochure alone | - | ↔ | - | - | - | - | - | - | - | -
Sharma, 2018 ^49^; N = 1000; LCS brochure with tear-off feature, indepth messaging from quit line staff vs LCS brochure alone | - | ↔ | - | - | - | - | - | - | - | -
Volk, 2020 ^41^; N = 516; “Lung Cancer Screening: Is It Right for Me?” video vs standard educational material | - | ↔ | - | ↔ | - | 87.2% (sufficient info) | - | - | - | ↑
Webster, 2023 ^37^; N = 298; Shouldiscreen.com print vs web | - | ↔ | - | ↔ | ↔ | No differences (preparedness or clarity) | - | ↔ | ↔ | ↔
Pre-Post
Crothers, 2016 ^23^; N = 45; Shouldiscreen.com, printed pamphlet | - | - | - | - | - | - | - | - | - | ↑
Hoffman, 2018 ^40^; N = 30; “Lung Cancer Screening: Is It Right for Me?” video | - | - | - | ↓ | - | - | - | - | ↑ | ↑
Lau, 2015 ^39^; N = 60; Initial development of shouldiscreen.com | - | - | ↑ | ↓ | - | - | - | - | - | ↑
Lau, 2021 ^38^; N = 74; Shouldiscreen.com | - | - | ↑ | ↓ | - | - | - | - | - | ↑
Reuland, 2018 ^47^; N = 50; 6-min SAILS decision aid video | - | 10 participants | - | - | - | - | 1 participant | - | - | ↑
Strong, 2020 ^43^; Educational YouTube video on LCS | - | - | - | - | - | - | - | - | - | ↑
Studts, 2020 ^44^; Online educational narrative coupled with decisional regret exercise | - | - | - | ↓ | - | - | - | - | ↓ | -
Volk, 2014 ^42^; “Lung Cancer Screening: Is It Right for Me?” video | - | - | - | - | - | 94% would recommend to others | - | - | - | ↑

↑ mean scores increased after receiving intervention, in favor of intervention

↔ no difference between arms after receiving intervention

↓ mean scores decreased after receiving intervention, in favor of intervention

Abbreviations. ACS=American Cancer Society; LCS=lung cancer screening.

Table 11 Certainty of Evidence for Patient Education to Potentially Generate SDM Visit

Outcome | Measurement Tool; Follow-up | № of Participants (Studies) | Findings | Certainty | Importance
Receipt of Lung Cancer Screening | % receiving screening; 6 months | 516; (1 RCT)^41^ | 57/259 (22%) SDM vs 68/257 (26.5%) LCS brochure | ⊕⊕⊕⊕; High | “Lung Cancer Screening: Is It Right for Me?” video results in no difference in receipt of lung cancer screening compared with a 2-page brochure from a lung cancer advocacy group.
Receipt of Lung Cancer Screening | % receiving screening; 6 months | N = 298; (1 RCT)^37^ | 11.0% shouldiscreen.com web vs 11.2% shouldiscreen.com print | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of shouldiscreen.com web compared to shouldiscreen.com print on receipt of lung cancer screening.
Receipt of Lung Cancer Screening | % receiving screening; 4-6 months | 1469; (2 RCTs)^48,49^ | 41/734 (5.6%) LCS brochure + additional materials vs 40/735 (10.9%) LCS brochure alone | ⊕◯◯◯; Very low^c,d^ | The evidence is very uncertain on the effect of a LCS brochure + additional materials compared to a LCS brochure alone on receipt of lung cancer screening.
Concordance of Decision | Ottawa Decision Support Framework; 0 days | N = 60; (1 pre-post)^39^ | 23.7% concordant pre-intervention vs 59.3% concordant post-intervention | ⊕◯◯◯; Very low^e^ | The evidence is very uncertain on the effect of SDM tools on concordance of decision.
Concordance of Decision | Question from Decisional Conflict Scale; 6 months | N = 74; (1 pre-post)^38^ | 21% concordant pre-intervention vs 33% concordant post-intervention | ⊕◯◯◯; Very low^f,g^ | The evidence is very uncertain on the effect of SDM tools on concordance of decision.
Decisional Conflict/Regret | Decisional Conflict Scale (Informed and Values Clarity subscales); 1 week | N = 516; (1 RCT)^41^ | Mean difference −14.1 | ⊕⊕⊕⊕; High | “Lung Cancer Screening: Is It Right for Me?” video results in less decisional conflict/regret compared with 2-page brochure from lung cancer advocacy group.
Decisional Conflict/Regret | Health Care Decisions Scale; 4 months | N = 298; (1 RCT)^37^ | 2.9 shouldiscreen.com web vs 2.7 shouldiscreen.com print | ⊕◯◯◯; Very low^a,h^ | The evidence is very uncertain on the effect of shouldiscreen.com web compared with shouldiscreen.com print on decisional conflict and regret.
Distress/Anxiety | Author-developed; 4 months | N = 298; (1 RCT)^37^ | 52.2% shouldiscreen.com web vs 54.4% shouldiscreen.com print were distressed/anxious | ⊕⊕◯◯; Low^a^ | Shouldiscreen.com web may cause little to no difference compared with shouldiscreen.com print on distress/anxiety.
Quality of Communication | Author-developed; 1 week | N = 60; (1 RCT)^46^ | 73% SDM tool very satisfied vs 28% usual care, no difference in preparedness | ⊕⊕◯◯; Low^f,i^ | LungTalk may result in little to no difference in quality of communication compared with non-tailored LCS information sheet.
Quality of Communication | Author-developed; 4 months | N = 298; (1 RCT)^37^ | 25.6% shouldiscreen.com web vs 33.3% shouldiscreen.com print were confused by the material | ⊕◯◯◯; Very low^a,j^ | The evidence is very uncertain on the effect of SDM web compared with SDM print on quality of communication.

Notes. GRADE Working Group grades of evidence:

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Rated down 2 levels for study limitations (study rated high risk of bias).

b Rated down 1 level for imprecision (low event rate [around 10%]).

c Rated down 2 levels for study limitations (study rated high risk of bias).

d Rated down 1 level for imprecision (low event rate [around 5%]).

e Rated down 1 level for indirectness (study population included participants not eligible for LCS).

f Rated down 1 level for indirectness (not comprehensive scale).

g Rated down 2 levels for imprecision (study did not meet OIS, sample size >150).

h Rated down 1 level for imprecision (OIS not met, sample size <400).

i Rated down 1 level for study limitations (study rated some concerns risk of bias).

j Rated down 1 level for indirectness (questions were not comprehensive of quality).

Abbreviations. RCT=randomized controlled trial; SDM=shared decision-making.

### SDM Tools Non-Specified

Two cohort studies used EMR data and ICD codes to investigate the effect of SDM in general (no specific tool or approach was reported) on receipt of or adherence to screening.^53,54^

One moderate RoB cohort study (N = 7,193) concluded that individuals with a documented SDM visit had “25% higher odds of adherence to annual lung cancer screening than those without SDM documentation (OR = 1.25, 95% CI [1.01, 1.54])” at 15-months follow-up (very low CoE, Table 12).^53^

One high RoB cohort study (N = 19,221) analyzed retrospective data to determine if there was an association between the SDM clinician specialty and the receipt of lung cancer screening. Compared with family physicians, the adjusted odds ratio of undergoing screening after an SDM visit was significantly higher with a radiologist (OR = 9.09, 95%CI [4.2, 19.9]) or a nurse practitioner (OR = 1.70, 95% CI [1.4, 2.1]). However, there was little to no difference with a pulmonary specialist (OR = 0.84. 95% CI [0.7, 1.0]) (very low CoE, Table 12). This study also reported adjusted odds ratios of undergoing screening by race, finding little to no difference in receipt of lung cancer screening in Black (OR = 0.87, 95% CI [0.7, 1.1]) or Hispanic (OR = 0.86, 95% CI [0.6, 1.2]) individuals, when compared with non-Hispanic White individuals.^54^

Table 12 Certainty of Evidence for SDM Tools Non-Specified

Outcome | Measurement Tool; Follow-up | Total № of Participants (Studies) | Findings | Certainty | Importance
Adherence | Participants with complete lung cancer screening claim within 15 months of SDM claim | N = 7193; (1 observational)^53^ | OR = 1.25, 95% CI [1.01, 1.54] | ⊕◯◯◯; Very low^a^ | The evidence is very uncertain on the effect of radiologists, nurse practitioners, or pulmonary specialists providing SDM compared with family physicians on adherence to lung cancer screening.
Receipt of Lung Cancer Screening | Participants with complete lung cancer screening claim within 3 months of SDM claim | N = 19,221; (1 observational)^54^ | Radiologist: OR = 9.09, 95% CI [4.16, 19.85]; Nurse practitioner: OR = 1.70, 95% CI [1.42, 2.05]; Pulmonary specialist: OR = 0.84, 95% CI [0.70, 1.01] | ⊕◯◯◯; Very low^a^ | The evidence is very uncertain on the effect of clinician providing SDM visit on receipt of lung cancer screening.

Notes. GRADE Working Group grades of evidence:

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 1 level for study limitations (rated some concerns or moderate risk of bias).

Abbreviations. CI=confidence interval; OR=odds ratio; SDM=shared decision-making.

## KEY QUESTION 2 ANY SDM TOOL OR DECISION AID COMPARED WITH USUAL CARE

Four studies (3 RCTs^27,30,35^ and 1 cohort study^26^) evaluated SDM compared with usual care. All found higher LCS with SDM. Walsh evaluated a tablet-based tool provided to patients in clinic prior to their primary care appointment. Authors randomized 78 individuals but evaluated 66 participants who completed baseline and follow-up surveys (1.5% of those initially contacted and meeting preliminary eligibility criteria). They reported that 4/32 (13%) completed LCS among controls versus 11/34 (32%) in the intervention group (p = 0.01) (4/41; 9.8% vs 11/37; 39.7% among those initially randomized) (very low CoE, Table 13).^35^

The other 2 RCTs included (or primarily evaluated) care coordinators or patient navigators in addition to SDM. DiCarlo evaluated outreach contact (OC) with mailed LCS information, a print decision aid, and contact with care coordinator to review material, assess LCS interest, and offer to schedule an LCS appointment alone or with additional interactive Decision Counseling (OC-DC) with a 10-minute interactive decision support software application versus usual care (UC).^27^ The third RCT by Percac-Lima evaluated a patient LCS navigation program among people who currently smoke. Navigators trained in motivational interviewing contacted patients to determine LCS eligibility, introduce LCS-SDM, provide brief smoking cessation counseling, schedule appointments with primary care clinicians, and help overcome barriers obtaining LCS (including translation, insurance, and transportation), communicating findings, and ensuring follow-up. Primary care clinicians received education about LCS guidelines, SDM, and LCS ordering but did not receive patient navigator support.^30^ Across both of these studies, 127/999 (12.7%) of those who received SDM tools received screening versus 100/2548 (3.9%) of those in usual care (low CoE, Table 13).

The cohort study by Bittner Fagan evaluated the online decision-aid program Decision Counseling Program (DCP) delivered by telephone via a trained decision counselor plus mailed follow-up educational material and additional SDM discussion with either PCP or LCS program staff to age-eligible people who currently smoke. Out of 1,359 potentially eligible patients, 336 could be contacted and 80 agreed to participate. LCS at 1 year was conducted in 29/64 (45.3%) of those who completed counseling versus 0/16 who did not (very low CoE, Table 13).^26^ Overall, evidence is sparse on the independent effects of SDM on LCS or other outcomes.

Table 13 Certainty of Evidence for Any SDM Tool Compared With Usual Care

Outcome | Measurement Tool; Follow-up | Total № of Participants (Studies) | Findings | Certainty | Importance
Receipt of Lung Cancer Screening | % receiving screening; 280 days – 1 year | N = 3,547; (2 RCTs)^27,30^ | 127/999 (12.7%) SDM tools vs 100/2548 (3.9%) usual care | ⊕⊕◯◯; Low^a,b^ | SDM tools may result in increased receipt of lung cancer screening compared with usual care.
Receipt of Lung Cancer Screening | % receiving screening; 2 months | N = 66; (1 RCT)^35^ | 32% LungCare vs 13% control | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of LungCare on receipt of lung cancer screening compared with usual care.
Receipt of Lung Cancer Screening | # completed LDCT within 1 year of SDM appointment | N = 80; (1 cohort)^26^ | 45.3% telephone DCP with counselor plus mailed educational material plus SDM discussion with PCP or LCS program vs 0% usual care | ⊕◯◯◯; Very low^a,d^ | The evidence is very uncertain on the effect of combined telephone DCP with counselor plus mailed educational material plus SDM discussion with PCP or LCS program on receipt of LCS compared with usual care.

Notes. GRADE Working Group grades of evidence:

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Rated down 1 level for study limitations (study rated some concerns RoB).

b Rated down 1 level for imprecision (event rate too low).

c Rated down 2 levels for imprecision (OIS not met, study had sample size <100).

d Rated down 1 level for study limitation (study rated moderate RoB).

Abbreviations. DCP=decision counseling program; LCS=lung cancer screening; PCP=primary care physician; RCT=randomized controlled trial; SDM=shared decisionmaking.

## KEY QUESTION 2 EVIDENCE FROM RCTS

Here, we summarize the evidence identified from eligible RCTs (k = 12) for efficacy/effectiveness and comparative effectiveness. Two RCTs assessed efficacy,^30,35^ 1 trial assessed both efficacy and comparative effectiveness,^27^ and 9 trials assessed comparative effectiveness (Table 14).^19,31,37,41,45,46,48–50^ One RCT included an intervention that involved a conversation with a physician and the utilization of a decision aid.^31^ Two RCTs included interventions that non-physician health care workers used to help guide SDM discussions.^27,30^ Two RCTs included patient-facing tools or materials that were used prior to or during an SDM visit.^19,35^ The remaining 7 RCTs included interventions that were patient-facing tools or materials that were meant to generate an SDM visit.^37,41,45,46,48–50^ Receipt of LCS was the most commonly reported outcome where CoE was assessed (9 trials). Decisional regret/conflict (k = 4), communication quality (k = 3) and distress/anxiety (k = 2) were less frequently reported. Knowledge was reported in 8 RCTs.

Table 14 Outcomes Reported and Direction of Effect for RCTs

Author, Year; Sample Size; Intervention | Outcomes With Certainty of Evidence Assessments^**^ | | | | | | Outcomes Without Certainty of Evidence Assessments
Author, Year; Sample Size; Intervention | Adherence | Receipt of Lung Cancer Screening | Concordance of Decision | Decisional Conflict/Regret | Distress/Anxiety | Overall Quality of Communication | Receipt of Additional Tests/Procedures | Satisfaction With Decision | Participant Need for Additional Information | Knowledge
Effectiveness
DiCarlo, 2022 ^27^; N = 2376; Reviewed mailed material including printed Option Grid ™ decision aid with care coordinator, with or without additional review of Decision Counseling Program vs usual care | - | ↑ * | - | - | - | - | - | - | - | -
Walsh, 2023 ^35^; N = 66; LungCare delivered on tablet in waiting room prior to visit vs usual care | - | ↑ | - | - | - | - | - | - | - | ↑
Percac-Lima, 2018 ^30^; N = 1200; Navigators contacted patients about SDM vs usual care | - | ↑ | - | - | - | - | ↔ | - | - | -
Comparative Effectiveness – Mode of Delivery
Robichaux, 2023 ^48^; N = 469 Mailed letter, face mask, LCS - brochure, & story about Native American traditional medicine vs LCS brochure alone | - | ↔ | - | - | - | - | - | - | - | -
Webster, 2023 ^37^; N = 298; Shouldiscreen.com print vs web | - | ↔ | - | ↔ | ↔ | No differences (preparedness or clarity) | - | ↔ | ↔ | ↔
Sharma, 2018 ^49^; N = 1000; LCS brochure with tear-off feature, in-depth messaging from quit line staff vs LCS brochure alone | - | ↔ | - | - | - | - | - | - | - | -
Comparative Effectiveness – Decision aid vs. educational tool
Schapira, 2023^19^; N = 140; Lung Cancer Screening Decision Tool (LCSDecTool) used independently before clinic visit vs general information on cancer screening + USPSTF lung and other cancer guideline | - | ↑ | - | ↔ | ↔ | - | - | - | - | ↑
Carter-Haris, 2020 ^46^; N = 60; LungTalk vs generic information sheet without LCS developed by ACS | - | - | - | - | - | 73% very satisfied (intervention), 28% very satisfied (comparator) | - | - | - | ↑
Clark, 2022 ^45^; N = 348; Video decision aid about incidental findings vs video aid w/o incidental findings | - | - | - | - | - | - | - | - | - | ↑
Fraenkel, 2015 ^50^; N = 253; Education on screening via numbers vs. numbers + icons vs numbers + slides | - | - | - | - | - | - | - | - | - | ↑
Volk, 2020 ^41^; N = 516; “Lung Cancer Screening: Is It Right for Me?” video vs standard educational material | - | ↔ | - | ↔ | - | 87.2% (sufficient info) | - | - | - | ↑
DiCarlo, 2022 ^27^; N = 628; Reviewed mailed material including printed Option Grid decision aid with care coordinator, with versus without additional review of Decision Counseling Program | - | ↔ * | - | - | - | - | - | - | - | -
Comparative Effectiveness – Decision aid vs Decision Aid
Sferra, 2021 ^31^; N = 237; Option Grid vs Shouldiscreen.com | - | - | - | ↔ | - | ↔ | - | - | - | ↔

Notes.

* Study compared 2 groups of SDM against usual care and found a statistically significant difference. However, there no statistically significant difference between the 2 SDM groups.

** These outcomes were priority ranked to identify the top 6 outcomes using a forced choice ranking including at least 1 “harm” to have certainty of evidence performed.

↑ mean scores increased after receiving intervention, in favor of intervention

↔ no difference between arms after receiving intervention

↓ mean scores decreased after receiving intervention, in favor of intervention

Abbreviations. LCS=lung cancer screening; SDM=shared decision-making.

### Efficacy/Effectiveness Trials

The 3 trials compared different decision aids, processes, mode of delivery, and targeted individuals (patient and/or provider) (Table 15).^27,30,35^ Interventions included a video administered on a touch tablet titled LungCare plus care coordination,^35^ outreach with mailed educational information with or without a telephone administered tool called Decision Counseling,^27^ and a patient navigation program with education materials.^30^ All had a usual care control. The studies reported few outcomes in common, however all reported LCS uptake (Table 16). One trial reported receipt of additional tests or procedures^30^ and another trial reported LCS knowledge.^35^ All 3 RCTs reported that those in the intervention arm had a significantly higher uptake of LCS than those in the control arm.^27,30,35^ The single trial that measured knowledge found that those in the intervention arm had significantly higher knowledge scores than the usual care arm.^35^

One trial^30^ which reported the number of individuals that required additional testing or procedures found, “In the intervention group, 12 (12.8%) patients had Lung-RADS 3 findings and required a six–month follow up compared to 6 (8.7%) in the control group. Seven (7.4%) in the intervention group and 6 (9.6%) in control patients had Lung-RADS 4 finding and required immediate follow-up. The number of additional diagnostic tests post-screening was similar in both groups…”

Table 15 Efficacy RCT Study Characteristics

Author, Year Risk of Bias Follow-Up | Intervention | Comparator | Mode of Delivery; Patient or Provider Facing | Tool Domains
Walsh, 2023 ^35^; Some concerns; 2 months | LungCare Video provided to patient on tablet in waiting room | Usual care | Web-video; Patient-facing | Eligibility for lung cancer screening; what screening is; individual risk for lung cancer screening; where to get screening; time commitment; harms
DiCarlo, 2022 ^27^; Some concerns; 280 days | Outreach with mailed educational information plus telephone Decision Counseling Program | Usual care | Person and print; Patient and Provider facing | Eligibility for lung cancer screening; what screening is; harms
Percac-Lima, 2018 ^30^; Some concerns; 1 year | A patient navigation program that included SDM | Usual care | Person and print; Provider facing | Eligibility for lung cancer screening; what screening is; harms

Table 16 Certainty of Evidence for SDM Tools versus Usual Care (Effectiveness RCTs)

Outcome | Measurement Tool; Follow-up | Total № of Participants (Studies) | Findings | Certainty | Importance
LCS Navigator Facing
Receipt of Lung Cancer Screening | % receiving screening; 280 days – 1 year | N = 3,547; (2 RCTs)^27,30^ | 127/999 (12.7%) SDM tools plus care coordination vs 100/2548 (3.9%) usual care | ⊕⊕◯◯; Low^a,b^ | SDM tools combined with care coordination may result in increased receipt of LCS compared with usual care.
Patient Facing During or Prior To Visit
Receipt of Lung Cancer Screening | % receiving screening; 2 months | N = 66; (1 RCT)^35^ | 32% LungCare vs 13% usual care | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of LungCare on receipt of lung cancer screening compared with usual care.

Notes. GRADE Working Group grades of evidence:

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 1 level for study limitations (rated some concerns, moderate, or high risk of bias).

b Rated down 1 level for imprecision (event rate too low).

c Rated down 2 levels for imprecision (OIS not met,sample size <150).

### Comparative Effectiveness Trials

Ten RCTs assessed comparative effectiveness^19,27,31,37,41,45,46,48–50^; 8 of the interventions were patient facing^19,37,41,45,46,48–50^ and 2 were meant to be viewed by both the patient and health care provider.^27,31^ Very few of the RCTs utilized the same SDM intervention tools; only 2 RCTs included shouldiscreen.com as one of the tools (as an intervention or comparator). The remaining RCTs included a variety of tools, including author-derived tools. In the broadest sense, the trials compared author-defined decision aids to tools or activities described as educational materials/activities or to the decision aid delivered in a different modality or format. Three trials assessed mode of delivery by comparing the same decision aid delivered in a different mode or format.^37,48,49^ The remaining 7 trials compared the decision aid to an educational tool/material/activity.^19,27,31,41,45,46,50^ Study characteristics are provided in Table 17. Certainty of evidence ratings for selected outcomes are reported in Table 18.

#### Trials Comparing Mode or Intensity of Delivery (Same Intervention)

Three trials compared the same tool but with changes to the intensity of the intervention or mode of delivery. Robichaux, 2023 investigated how the addition of additional outreach to a mailer and social media campaign would influence shared decision-making in an urban Native American clinic.^48^ Webster, 2023 investigated differences in uptake and understanding when shouldiscreen.com was provided in an online or print format.^37^ Finally, Sharma, 2018 investigated the impact of including in-depth messaging from quitline staff with a mailed brochure in comparison to just receiving the mailed brochure.^49^ All 3 trials measured the receipt of lung cancer screening and all 3 found that there was no significant increase in the receipt of lung cancer screening when comparing different modalities or intensity of the SDM tool.

Webster, 2023^37^ also measured decisional conflict, distress/anxiety, quality of communication, satisfaction with decision, participant need for additional information, and knowledge and found no significant difference between those that viewed shouldiscreen.com virtually or in print form.

#### Trials Comparing Decision Aids to an Educational Tool or Another Decision Aid

Six RCTs compared an author defined decision aid to a traditional educational tool for LCS.^19,27,41,45,46,50^ Another RCT, by Sferra, 2021,^31^ compared 2 different decision aids, Option Grid and shouldiscreen.com. Five of the 6 trials measured knowledge.^19,41,45,46,50^ Of the 5 trials that compared a decision aid to an educational tool, the authors found a significant increase in knowledge scores among those that were exposed to the decision aid compared with those provided the educational tool. The single trial^31^ that compared 2 decision aids found no difference in knowledge scores between the 2 groups.

Three RCTs comparing a decision aid with an educational tool measured receipt of LCS.^19,27,41^ Two found no significant difference between those exposed to a decision aid versus those exposed to an educational tool and the proportion of participants that chose to undergo LCS. ^27,41^ The third trial by Shapira, 2023 found that those exposed to the decision aid (LCSDecTool) were more likely to undergo LCS than those exposed to general information on cancer screening and the United States Preventive Task Force screening guidelines for breast, colon, cervical, and lung cancer.^19^

Two trials measured decisional conflict or regret and both found no significant difference between the intervention and comparator arms.^31,41^ Volk, 2020 compared Lung Cancer Screening: Is it Right for Me? with a standard educational tool from a lung cancer advocacy group,^41^ while Sferra, 2021 compared exposure to shouldiscreen.com to exposure to Option Grids.^31^

Three of the trials assessed quality of communication using author-developed surveys; 2 of the trials reported 73% and 87.2% were satisfied with the information provided in the decision aid.^41,46^ The third trial reported no significant difference in assessment of the quality of the decision aid when comparing shouldiscreen.com to Option Grids.^31^

Table 17 Comparative Effectiveness RCTs Study Characteristics

Author, Year; Risk of Bias; Follow-Up | Intervention | Comparator | Mode of Delivery; Patient or Provider Facing | Tool Domains
Robichaux, 2023 ^48^; Low; 6 months | Mailed Letter, face mask, LCS brochure, story about Native American traditional medicine, follow-up text message and second mailing | Mailed letter, face mask, LCS brochure & story about Native American traditional medicine | Print (mailed) and text message; Patient facing | Eligibility for LCS, what screening is, individual risk for LC, and where to get screening
Webster, 2023 ^37^; High; 4 months | Shouldiscreen.com | Print version of shouldiscreen.com | Web; Patient facing | Eligibility for LCS, what screening is, individual risk for LC, cost, where to get screening, time commitment, harms, and other risk factors
Schapira, 2023 ^19^; Low; 9 months | LCSDecTool | 10-page general information on cancer prevention and the USPSTF screening guidelines for breast, colon, cervical, and lung cancer | Web; Patient facing | Eligibility for LCS, what screening is, individual risk for LC, cost, where to get screening, time commitment, harms, and other risk factors
DiCarlo, 2022 ^27^; Some concerns; 280 days | Outreach contact plus LCS information plus telephone-administered decision counseling | Outreach contact plus with LCS information (no telephone-administered decision counseling) | Print (mailed); Patient facing | Eligibility for LCS, what screening is, and harms
Clark, 2022 ^45^; Some concerns; 0 days | 4 5-minute video covering the benefits and harms of screening – including information on incidental findings | 4-minute video covering the benefits and harms of screening – excluded the information on incidental findings | Video; Patient facing | What screening is, costs, and harms
Sferra, 2021 ^31^; Some concerns; 6 months | Optiongrid.org | Shouldiscreen.com | Web; Patient facing | Eligibility for LCS, what screening is, individual risk for LC, cost, where to get screening, time commitment, harms, and other risk factors
Carter-Harris, 2020 ^46^; Some concerns; 3 months | LungTalk (a computer tailored decision support tool (audio, video, and animation segments)) | Generic information sheet online about LCS developed by the American Cancer Society | Web; Patient facing | What screening is and harms
Volk, 2020 ^41^; Some concerns; 6 months | Lung Cancer Screening: Is it Right for Me? | Standard educational material brochure from a lung cancer advocacy group | Web; Patient facing | Eligibility for LCS, what screening is, harms, and other risk factors
Sharma, 2018 ^49^; High; 4 months | LCS brochure with a tear-off feature to promote contact with their health care provider with phone-based in-depth messaging coupled with in-depth messaging from quitline staff | LCS brochure with a tear-off feature to promote contact with their health care provider | Print (mailed); Patient facing | Eligibility for LCS, what screening is, and costs
Fraenkel, 2015 ^50^; High; 0 days | Numbers + a set of slides illustrating LDCT scans of 250 people in random order | Numbers + icon array or numbers only | Print; Patient facing | Harms

Abbreviations. LC=lung cancer; LCS=lung cancer screening; LCSDecTool=lung cancer screening decision tool; LDCT=low-dose computed tomography; SDM=shared decision-making.

Table 18 Certainty of Evidence for SDM Tools versus SDM Tool/Educational Aid (Comparative Effectiveness RCTs)

Outcome | Measurement Tool; Follow-up | Total № of Participants (Studies) | Findings | Certainty | Importance
Clinician Facing
Decisional Conflict or Regret | Ottawa Decision Regret Scale; 6 months | N = 237; (1 RCT)^31^ | Mean scores 6.0 (Option Grids) vs 10.2 (shouldiscreen.com), p = 0.02 | ⊕⊕◯◯; Low^a,b^ | Option Grids may result in less decisional conflict or regret compared with shouldiscreen.com.
Quality of Communication | CollaboRATE; 6 months | N = 237; (1 RCT)^31^ | Mean scores 97.4% (Option Grids) vs. 98.6% (shouldiscreen.com), p = 0.6 | ⊕⊕◯◯; Low^a,b^ | There may be little to no difference in quality of communication in SDM using Option Grids compared with shouldiscreen.com.
Patient Facing During or Prior To Visit
Receipt of Lung Cancer Screening | % receiving screening; 6 months | N = 140; (1 RCT)^19^ | 18% difference between LungCare and usual care | ⊕⊕◯◯; Low^c^ | LCSDecTool may result in increased lung cancer screening compared with usual care.
Decisional Conflict/Regret | Decisional Conflict Scale; 3 months | N = 140; (1 RCT)^19^ | LungCare 24.2 (20.8, 27.6) vs usual care 27.5 (23.3, 31.7) with a between group difference of −2.9 (−8.9, 3.0), p = 0.33) | ⊕⊕◯◯; Low^c^ | LCSDecTool may result in little to no difference in distress/anxiety compared with usual care.
Distress/Anxiety | Strate Trait Anxiety Index; 3 months | N = 140; (1 RCT)^19^ | No statistically significant difference between LungCare and usual care | ⊕⊕◯◯; Low^c^ | LCSDecTool may result in little to no difference in distress/anxiety compared with usual care.
Patient Facing to Generate a Visit
Receipt of Lung Cancer Screening | % receiving screening; 6 months | N = 516; (1 RCT)^41^ | 57/259 (22%) SDM tools vs 68/257 (26.5%) usual care | ⊕⊕⊕⊕; High | “Lung Cancer Screening: Is It Right for Me?” video results in no difference in receipt of lung cancer screening compared with a 2-page brochure from a lung cancer advocacy group.
Decisional Conflict / Regret | Decisional Conflict Scale; 1 week | N = 516; (1 RCT)^41^ | Mean difference −14.1 | ⊕⊕⊕⊕; High | “Lung Cancer Screening: Is It Right for Me?” video results in less decisional conflict/regret compared with 2-page brochure from lung cancer advocacy group.
Quality of Communication | Author-developed; 1 week | N = 60; (1 RCT)^46^ | 73% SDM tool very satisfied vs 28% usual care, no difference in preparedness | ⊕⊕◯◯; Low^a,e^ | LungTalk may result in little to no difference in quality of communication compared with nontailored LCS information sheet.
Receipt of Lung Cancer Screening | % receiving screening; 6 months | N = 298; (1 RCT)^37^ | 11.0% SDM web vs 11.2% SDM print | ⊕◯◯◯; Very low^b,c^ | The evidence is very uncertain on the effect of SDM web compared to SDM print on receipt of lung cancer screening.
Decisional Conflict / Regret | Health care Decisions Scale; 4 months | N = 298; (1 RCT)^37^ | 2.9 SDM web vs 2.7 SDM print | ⊕◯◯◯; Very low^b,d^ | The evidence is very uncertain on the effect of SDM web compared to SDM print on decisional conflict and regret.
Distress/Anxiety | Author-developed; 4 months | N = 298; (1 RCT)^37^ | 52.2% SDM web vs 54.4% print were distressed/anxious | ⊕⊕◯◯; Low^b^ | shouldiscreen.com web may cause little to no difference compared with shouldiscreen.com print on distress/anxiety.
Quality of Communication | Author-developed; 4 months | N = 298; (1 RCT)^37^ | 25.6% SDM web vs 33.3% SDM print were confused by the material | ⊕◯◯◯; Very low^b,e^ | The evidence is very uncertain on the effect of SDM web compared with SDM print on quality of communication.

Notes. GRADE Working Group grades of evidence:

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Rated down 1 level for study limitations (study rated some concerns risk of bias).

b Rated down 2 levels for study limitations (study rated high risk of bias).

c Rated down 1 level for imprecision (low event rate [around 10%]).

d Rated down 1 level for imprecision (OIS not met, sample size <400).

e Rated down 1 level for indirectness (questions were not comprehensive of quality).

Abbreviations. LCSDecTool=lung cancer screening decision tool; RCT=randomize controlled trial; SDM=shared decision-making.

## KEY QUESTION 3 HARMS OF THE COMMUNICATION STRATEGIES, TOOLS, AND/OR APPROACHES

No studies reported on “author-defined harms.” Based on discussion with our operational partners and TEP, we categorized anxiety and decisional regret as harms. These findings are reported under KQ2.

## KEY QUESTION 4 BARRIERS AND FACILITATORS

Nine studies captured barriers and facilitators related to LCS SDM. Eight of these studies were qualitative study designs.^21,22,55–60^ The ninth was a mixed-method design, employing a pre-post study design that investigated the impact of SDM and qualitative interviews to identify barriers and facilitators to implementing or maintaining SDM.^18^ All but 1 study^18^ interviewed health care providers, and 4 studies interviewed patients (Table 19).^18,21,22,57^

While all 9 studies assessed health care professionals’ or patients’ perceptions of SDM, not all authors assessed the implementation of a specific SDM tool. All included study populations had made use of an SDM tool; 5 studies^18,21,56–58^ identified a specific tool and the remaining 4 assessed SDM as a concept, as multiple tools were in place.^22,55,59,60^ Studies varied in their analytic approach to summarize themes identified from the interviews (see Appendix Table 11).

We provide the extracted qualitative themes grouped by CFIR domains and constructs. Table 20 provides a summary of the themes identified in the included studies coded to each CFIR domain. Two domains appeared repeatedly across the studies. The first domain was resource availability,^55,56,58,60^ with time constraints frequently referenced as a barrier to implementing SDM. An example of this constraint from Lowery, et al follows: “Most PCPs reported needing 1 to 2 minutes to discuss LCS but frequently voiced not having 1 to 2 minutes during a visit because of patient-specific needs that were a higher priority.”^56^ The second CFIR domain was innovation recipients, with a number of studies reporting a theme around patients’ reticence and lack of engagement with SDM^22,55,57,59,60^ and patients’ negative response to the SDM.^18,21,59,60^ Melzer, et al reported “Lack of patient engagement in the process of decision making was a barrier identified by all clinician types. A large number of patients, particularly older patients, requested a firm recommendation.”^60^ Overall, barriers were reported with more frequency than facilitators, with themes related to facilitation often recommending or praising the inclusion of a decision aid during the SDM encounter.^55,58,61^

Of the included qualitative studies, 5 captured a VA patient population or VA health care providers.^21,22,55,56,60^ Themes that emerged included a culture receptive to SDM to promote LCS screening: “The data supports so strongly that [LCS] is beneficial, that it doesn’t seem like there’s much of a decision.”^55^ Barriers related to available resources (both clinicians and LCS navigators and tools), prioritization among other clinic demands and expectations, and innovation among both the deliverers and the recipients.

Table 19 Summary Characteristics of Eligible Qualitative Studies

Author, Year | ROB | Health Care Provider Interview | Patient Interview | N | Number of Sites | Qualitative Approach | SDM Implementation Evaluated
Herbst * , 2023 ^55^ | Low | ✔ | | 15 | 7 | Ethnographic | Any SDM tool used currently in clinic
Lowery * , 2022 ^56^ | High | ✔ | | 33 | 8 | Inductive thematic content analysis | SDM tool called Decision Precision
Schapira * , 2022 ^21^ | High | ✔ | ✔ | 42 | 1 | Thematic analysis | SDM tool called LCSDecTool
Martinez, 2022 ^57^ | Low | ✔ | ✔ | 40 | 1 | Grounded theory approach | LCS-LDCT Smart Set (a pre-programmed Epic tool)
Reese, 2022 ^58^ | Low | ✔ | | 14 | 1 | Interviews coded using the Unified Theory of Acceptance and Use of Technology (UTAUT) and Social Cognitive Theory (SCT) models | Electronic decision aid
Abubaker-Sharif, 2022 ^59^ | High | ✔ | | 16 | 1 | Thematic analysis | Any SDM tool (used Decision Counseling Program as an example)
Melzer * , 2020 ^60^ | Low | ✔ | | 24 | 3 | Directed content analysis | Any SDM tool used currently in clinic
Han, 2019 ^18^ | Low | | ✔ | 17 | 1 | Inductive qualitative methods | A lung cancer risk calculator
Wiener * , 2018 ^22^ | Moderate | ✔ | ✔ | 52 | 4 | Directed content analysis | Any SDM tool used currently in clinic

Notes.

* Included VA health care professionals or Veterans as part of the study population.

Table 20 Barriers and Facilitators Identified in Qualitative Interviews of SDM Deliverers and Recipients

CFIR Domain; CFIR Construct | ☹ Barrier; ☺ Facilitator | Barrier or Facilitator Description
I. Innovation Domain
Adaptability | ☹ ☺ | 3 studies reported that tailoring of the information to the participant was important,^22,59,60^ including developing tools in other languages.^59^
Complexity | ☹ | 1 study noted the complexity of SDM, and the multiple factors needed to know to guide the conversation (patient education, elicitation of personal values, knowing participant risk).^59^
Design | ☹ | 2 studies reported the design of the tool was a barrier (difficult to navigate and medical terminology difficult for patient to understand,^21^ inputting data during visit to calculate risk^56^).
Design | ☺ | 1 study suggested the use of any tool prior to a visit would enable SDM.^58^
Evidence Base | ☹ | 1 study reported clinicians were surprised by low specificity of LDCT and frequency of false positives resulting in unnecessary procedures and major complications.^58^
II. Outer Setting Domain
External Pressure; Performance Measurement | ☹ ☺ | 2 studies reported organizational priorities or pressure to meet organizational goals influenced their decision to engage in SDM (some felt pressure to incorporate it, while others prioritized other organization goals over SDM).^56,58^
External Pressure; Performance Measurement | ☹ | 1 study reported clinicians felt pressure to demonstrate the value of a dedicated LCS coordinator.^55^
Local Attitudes | ☹ | 2 studies reported clinicians felt smoking history documentation in the EHR was inaccurate.^57,58^
III. Inner Setting Domain
Access to Knowledge and Information | ☹ | 2 studies reported clinicians had little or no knowledge of health care system initiatives^55^ or lacked knowledge about logistics of an LCS program.^59^
Available Resources | ☹ | 4 studies reported that time constraints were a significant barrier.^55,56,58,60^
Available Resources | ☺ | 1 study suggested a decision aid would benefit patients and providers.^57^
Communications | ☹ | 1 study reported lack of communication about goals and structure led to confusion about how to implement elements of a lung cancer screening program.^55^
Culture | ☹ | 1 study reported clinicians perceived the value of screening as high, therefore limited information about harms and emphasized benefits during SDM discussions.^55^
Culture | ☹ | 1 study noted the difficulty in having screening conversations with patients who are unlikely to be receptive.^59^
Relative Priority | ☹ | 3 studies noted that SDM may not be as high a priority compared to competing demands such as other preventive screening or patient specific needs.^55,56,58^
Structural Characteristics; IT Infrastructure | ☺ | 2 studies reported integrating the SDM tool into the EHR would be beneficial, to obtain patient information and facilitate reminders.^55,58^
Structural Characteristics; IT Infrastructure | ☹ | 1 reported difficulties in integration, especially regarding ordering LDCT.^57^
IV. Individuals Domain
Capability | ☹ | 3 studies reported on the clinicians’ perceived capability to engage in SDM, including conflation of SDM with patient education,^55^ difficulties with eligibility criteria,^57^ and being unaware of insurance requirements or reimbursements.^58^
Innovation Deliverers | ☹ | 1 study reported that clinicians’ personal experiences led to promotion of screening, regardless of guidelines recommending screening.^55^
Innovation Deliverers | ☹ ☺ | 1 study reported clinicians had mixed feelings about using decision aids (facilitated discussion but risk information served as a barrier to engaging patients).^22^
Innovation Recipients | ☹ | 5 studies reported on lack of patient engagement in SDM, or readiness to accept clinicians’ recommendation without discussion.^22,55,57,59,60^
Innovation Recipients | ☹ | 4 studies reported patients had negative affective responses to SDM and LCS (eg, patients “didn’t want to know”).^18,21,59,60^
Innovation Recipients | ☹ | 3 studies reported that clinicians perceived patients’ awareness and knowledge about LCS was limited.^21,57,59^
Innovation Recipients | ☺ | 1 study reported that clinicians agreed ensuring a screening decision in line with patient’s values was important.^60^
Innovation Recipients | ☹ ☺ | 1 study reported patients had mixed feelings about use of decision aids (some found them useful while other found information on harms off-putting).^22^
Innovation Recipients | ☹ | 1 study reported on the frequency in which SDM for LCS should happen, and when patients may be receptive.^57^
Innovation Recipients | ☹ ☺ | 1 study reported that patient accounts reflected a range of information received about LCS (eg, minimal information on harms given and then experienced an unexpected outcome vs comprehensive information given).^22^
Need | ☹ | 1 study reported patients smoking history made LCS compulsory, and a rationale to bypass SDM.^55^

Notes. CFIR=Consolidated Framework for Implementation Research; EHR=electronic health record; IT=information technology; LCS=lung cancer screening; LDCT=low-dose computed tomography; SDM=shared decision-making.