# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42024511257 (https://www.crd.york.ac.uk/prospero/display_record.php?RecordID=511257)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

Key Question 1 | What communication strategies, tools, and/or approaches used for shared decision making (SDM) in lung cancer screening are reported in the literature?
Key Question 2a | What is the effectiveness and comparative effectiveness of communication strategies, tools, and/or approaches used to enhance SDM for lung cancer screening?
Key Question 2b | Does effectiveness vary by patient (i) or clinical setting (ii) characteristics:; i. age, race/ethnicity, comorbidities, current smoking status, socioeconomic status/education, residency, geographic region, rural/urban; ii. primary care, smoking cessation, prevention clinics, public forums
Key Question 3 | What are the harms of the communication strategies, tools, and/or approaches used to enhance SDM for lung cancer screening?
Key Question 4 | What are the barriers and facilitators of implementing different communication strategies, tools, and/or approaches for lung cancer screening SDM?

Study eligibility criteria are shown in the table below.

| Eligibility Criteria
| Inclusion Criteria | Exclusion Criteria
Population | Adults (≥ 18 years of age) in the US | Individuals considering lung cancer screening modalities other than LDCT (such as chest radiography); Populations at increased risk for lung cancer unrelated to smoking exposure/history (eg, non-Hodgkin’s lymphoma)
Intervention | Shared decision-making tools/aids | Non-lung cancer screening decision making tools/communication strategies/approaches
Comparator | Any
Outcomes | KQ1: Types of SDM stratified by patient decision aid or educational tool, tool format, and tool environment; KQ2:; - Patient experience (eg, quality of communication, satisfaction with decision, decisional conflict/regret, concordance of decision with patient’s values and preferences, distress/anxiety); - Participation in the screening program; - Receipt of lung cancer screening; - Receipt of additional tests/procedures for identified findings; - Adherence to subsequent screening; - Knowledge of screening benefit and harms; - Participant need for additional information; - Smoking behaviors; - Resource allocations/usage (eg, primary clinician time, additional clinical staff time, staff, patient time, medical media support, IT support); - Cost (eg, cost or cost effectiveness); KQ2b: (KQ2 outcomes stratified by the following effect modifiers); - Rural/urban; - Regional; - Ethnicity; - Health literacy; - Lung cancer risk; - Competing comorbidities; - Serious mental illness; KQ3: Any harm reported by study authors; KQ4:; - Barriers (staff time, patient time, cost, method of delivery, counseling required, care visits (eg, consult of visit to SDM appointment), language, readability/communication, access to care); - Facilitators (staff education, support from leadership, allocated time, ease of delivery, etc)
Timing | 2010 (post guidance for use of shared decision making for lung cancer screening) | < 2010
Setting | US Clinics, including community outreach | Hospice
Study Design | KQs 1–3: RCT, observational with comparator or quasi-experimental; KQ4: Observational | Systematic reviews, abstracts, conference proceedings, case studies, editorials

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched Embase, Medline, and CINAHL from January 2010 through December 6, 2023, using controlled vocabulary (MeSH, Emtree) and key words for lung cancer and decision making (see Appendix for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. English-language titles, abstracts, and full-text articles were independently reviewed by 2 reviewers, and a single yes response moved a citation forward to full text review. Full text review was completed independently by 2 reviewers and disagreements were resolved by consensus. If consensus could not be reached, a third member of the review team was consulted to mediate and make final determination.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Effect information and population, intervention, and comparator characteristics were abstracted from all included studies. As both RCTs and studies employing an observational design were eligible for inclusion, the internal validity (risk of bias [RoB]) of each included study was rated using one of the following tools according to its design: RoB 2.0,^12^ JBI Cohort RoB tool,^13^ JBI Quasi-Experimental RoB tool,^14^ or the CASP Qualitative Checklist.^15^ RoB was completed independently by 2 reviewers and a third reviewer was included if consensus could not be reached. All data abstraction was first completed by 1 reviewer and then checked; disagreements were resolved by consensus or discussion with a third reviewer (see Appendix for risk of bias ratings).

To synthesize the qualitative studies, we used the Consolidated Framework for Implementation Research framework (CFIR).^16^ Two reviewers independently coded each study by extracting relevant text and assigning to the respective CFIR domain (see Appendix for CFIR domains). Each of these codes and associated text were captured in Distiller. The 2 reviewers and other team members then met to review the extracted text and assign the final code by consensus. A priori codes were generated from CFIR. A best-fit framework synthesis was applied to adapt the frameworks and generate overarching themes reported in the evidence.^16^

## SYNTHESIS

As study design, methods, assessment tools, and outcome definitions varied widely across studies, we were unable to pool study results for the included outcomes. We provide a high-level summary of all the included studies. We then present evidence by whether the tool was a health care provider-facing tool (eg, used in clinic and meant to guide the discussion) or a patient-facing tool or material (eg, meant to inform the patient either prior to or during the visit but not guide discussion). Within the health care provider-facing tools, we stratified by whether the tool was meant to be used by a clinician or LCS navigator and patient. Within the patient-facing tools, we stratified by whether the tool was meant to be used prior to, or during, a scheduled SDM visit or if the tool was meant to generate a SDM visit. Studies that investigated tools or settings that did not fit into the previously mentioned category were summarized as “other” category. We separately reported results from RCTs and studies versus with usual care to gauge the sensitivity of findings to the study design and comparator employed.

Included qualitative studies are summarized separately in the results section, using tables to provide study characteristics and brief synopses of the study text supporting the identified theme.

### Strength of Evidence

After synthesizing available evidence, we rated the certainty of evidence (CoE) for each outcome based on the methodology and RoB of available studies, the consistency and certainty of findings, and the directness of outcomes (whether reported outcomes are relevant to patients and providers) using standard GRADE methodology.^17^ Of note, the CoE assessment starts at high for RCTs and begins at low for observational studies. Prior to results analyses, we conducted a ranking exercise among our content experts, operational partners, and TEP to determine which of the included outcomes were most important. Among the included outcomes, the following were ranked the top 6 and CoE ascertained: receipt of LCS, distress/anxiety, adherence to subsequent screening, concordance of decision with patient’s values and preferences, decisional conflict/regret, and quality of communication.

As noted above, studies varied in interventions, delivery modes, clinic settings, and whether interventions were patient- or health care professional-facing. We primarily assessed CoE for each outcome separately by these factors. To assess “effectiveness” of SDM overall, we also assessed CoE for studies of any SDM versus usual care (concurrent or pre-post comparisons) regardless of intervention, delivery mode, clinical setting, or targeted individual. Due to limited reporting on the outcomes of adherence to subsequent LCS, concordance of decision with patient’s values and preferences, and distress/anxiety, we focused this assessment on receipt of LCS, decisional conflict/regret, and quality of communication. We also separately reported results from RCTs.