# BACKGROUND

Despite declines in smoking rates in recent decades, over 230,000 new cases of lung and bronchus cancer will be diagnosed in the US in 2024, and 125,070 deaths attributable to lung cancer will occur in the same period.^1^ Both incidence and mortality have declined but lung cancer remains the leading cause of cancer deaths in the US. The 5-year survival rate for lung cancer remains low at 25% with a median age at death of 73 years.^1^ Lung cancer rates and mortality in the US are highest in non-Hispanic Black men. but markedly lower in Hispanic and non-Hispanic Asian/Pacific Islanders.^2^

The US National Lung Screening Trial (NLST) enrolled primarily men of White race, aged 55-74, who currently or formerly smoked heavily. Results of NLST found that 3 rounds of annual lung cancer screening (LCS) with low-dose CT scanning (LDCT) reduced lung cancer mortality during 7 years of follow-up. Absolute reductions persisted at 3.3 lung cancer deaths per 1,000 through 12 years of follow-up but were no longer statistically significant (95% CI [−0.2 to 6.8]). Harms identified during the trial included LDCT radiation-induced cancers, false positive results, incidental findings, short-term anxiety and distress, and possible overdiagnosis. Although randomized LDCT screening trials have consistently reported benefits, participants in these trials were generally younger, more highly educated, had less racial and ethnic diversity, and were less likely to be people currently smoking than the US screening-eligible population.^3^ Older adults in the US (including Veterans) also face higher risk of death from competing causes compared with trial participants.^3^

Despite concerns about unrepresentativeness, the above findings along with results from incidence and modeling studies led the US Preventive Services Task Force (USPSTF) to issue a 2021 update to its lung cancer screening recommendation with expanded indications for eligible populations: annual LCS screening with LDCT in adults aged 50–80 who have a 20 pack-year smoking history and currently smoke or have quit within the past 15 years. Discontinuation of screening is recommended once a person has not smoked for 15 years or develops a health problem that substantially limits life expectancy or the ability or willingness to have curative lung surgery.^4^ The new recommendations are also intended to reduce racial/ethnic disparities in LCS mortality and access to screening.

As noted by others,^3^ the US population eligible for lung cancer screening (including Veterans) may be less likely to benefit from early detection compared with participants in NLST and other key trials, given that they face a high risk of death from competing causes, such as heart disease and stroke.^5^ Additionally, data from the 2012 Health and Retirement Study showed a lower 5-year survival rate and life expectancy in screening-eligible persons compared with NLST participants. Because the likelihood of a net benefit of LCS is largely dependent upon an individual’s lung cancer risk and comorbidities, the requirement to ensure that patients are aware of both the benefits and harms prior to undergoing LCS was enacted. Shared decision-making (SDM), a process that involves both patients and clinicians in the decision-making process, is encouraged for potentially eligible individuals prior to LCS.^5^

SDM involves providing patients with information on treatment/testing options as well as chances of beneficial and harmful outcomes. SDM is also intended to give clinicians methods, and encourage them, to clarify and support patient preferences and values. SDM is considered particularly important in preference-sensitive decisions (when the decision to undergo a test/treatment may reasonably vary from patient to patient based on their individual weighting of benefits, harms, and values). In 2015 (updated in 2022), the Centers for Medicare and Medicaid Services (CMS) enacted a stipulation that counseling and SDM were a prerequisite for LCS to be reimbursable.^6,7^ Specifically CMS stated that “before the Medicare beneficiary’s first lung cancer LDCT screening, the beneficiary must receive a counseling and shared decision-making visit that meets all of the following criteria, and is appropriately documented in the beneficiary’s medical records: 1) Determination of beneficiary eligibility; 2) Shared decision-making, including the use of one or more decision aids; 3) Counseling on the importance of adherence to annual lung cancer LDCT screening, and impact of comorbidities and ability or willingness to undergo diagnosis and treatment; and 4) Counseling on the importance of maintaining cigarette smoking abstinence if former smoker; or the importance of smoking cessation if current smokers and if appropriate, furnishing of information about tobacco cessation interventions.” SDM has been defined as “an approach where clinicians and patients share the best available evidence when faced with the task of making decisions, and where patients are supported to consider options, to achieve informed preferences.”^8^ Several decision aids and educational tools have been developed for SDM in LCS and are designed to improve patient knowledge about lung cancer screening, reduce decisional conflict and regret, and enhance LCS uptake and long-term compliance among individuals most likely to have a benefit that exceeds harms. A key distinction between a decision aid and educational tool is that a patient decision aid is not meant to advise people to choose one option over another; instead, it is meant to provide people with information needed to make an informed and values-based decision.^9^

The Veterans Health Administration (VHA) serves approximately 9 million Veterans,^10^ many of whom are racial or ethnic minorities or members of other historically underserved populations. A large portion of these individuals are older male US Veterans with multiple comorbid conditions and are people who currently or formerly smoked. A higher proportion of Veterans are of Black race than the general US population. A study by Kinsinger et al in 2016 estimated that nearly 900,000 VHA patients would meet earlier 2013 USPSTF LCS eligibility criteria.^11^ The same analysis estimated that nearly half of eligible patients would likely agree to initial screening, and of these patients, more than half would require additional tracking. LCS requires an annual commitment from the patient to schedule and complete annual low dose CT scans. Additionally, resources are required to identify, counsel, track, and ensure adherence. LCS harms include false positive results and subsequent testing, identification of incidental findings, overdiagnosis, and radiation exposure. Therefore, harms may offset benefits in many and result in high resource use. Thus, SDM for potentially eligible individuals is meant to ensure patients referred for LCS have accurate information to make decisions concordant with clinical benefits and harms and individual preferences and values and to enhance long-term LCS adherence and follow-up among individuals undergoing LCS.

The VA’s National Center for Lung Cancer Screening (NCLCS) is tasked with equitably expanding LCS access to the estimated 1-1.5 million Veterans eligible under the updated USPSTF recommendations.^11^ Considerations for VA (and non-VA health care systems) include the resources necessary to identify and counsel eligible patients, track patients including evaluation of abnormal LDCT scans, and ensure adherence to annual screenings. NCLCS requested the present review of evidence on benefits and harms of SDM practices and strategies to inform policies on the use of formal decision aids.