# ABBREVIATIONS TABLE

Abbreviation: Definition
ACS: American Cancer Society
CASP: Critical Appraisal Skills Programme
CCT: Controlled clinical trial
CFIR: Consolidated Framework for Implementation Research
CINAHL: Cumulative Index to Nursing and Allied Health Literature
CMS: Centers for Medicare and Medicaid Services
CoE: Certainty of evidence
CT: Computed tomography
DCP: Decision Counseling Program
DCS: Decisional Conflict Scale
DCS-LL: Decisional Conflict Scale – Low Literacy
HER: Electronic health record
EMR: Electronic medical record
ESP: Evidence Synthesis Program
FAQ: Frequently asked questions
GRADE: Grading and Recommendations, Assessment, Development, and Evaluations
ICD: International Classification of Diseases
IPDAS: International Patient Decision Aid Standards
IQR: Interquartile range
IT: Information technology
JBI: Joanna Briggs Institute
KQ: Key question
LCS: Lung cancer screening
LCSDecTool: Lung Cancer Screening Decision Tool
LDCT: Low-dose computed tomography
LungRADS: Lung CT Screening Reporting & Data System
Mo: Month
MRI: Magnetic resonance imaging
NA: Not applicable
NCI: National Cancer Institute
NCLCS: National Center for Lung Cancer Screening
NELSON: Nederlands–Leuvens Longkanker Screenings Onderzoek (Dutch-Belgian lung cancer screening trial)
NIH: National Institute of Health
NLST: National Lung Screening Trial
No: Number
NR: Not reported
OR: Odds ratio
PCP: Primary care provider
PDA: Patient decision aid
PET: Positron emission tomography
PLCO: Prostate, Lung, Colorectal, and Ovarian Cancer Screening Trial
PROSPERO: International Prospective Register of Systematic Reviews
RCT: Randomized controlled trial
RoB: Risk of bias
SAILS: Supporting Appropriate Implementation of Lung Cancer Screening
SCT: Social Cognitive Theory
SD: Standard deviation
SDM: Shared decision-making
SE: Standard error
SES: Socioeconomic status
TEP: Technical Expert Panel
UNC: University of North Carolina
USPSTF: United States Preventative Services Task Force
UTAUT: Unified Theory of Acceptance and Use of Technology
VA: Veterans Affairs
VAS: Visual analog scale
VHA: Veterans Health Administration
Wk: Week
Yr: Year