# References

1 Hu JC, Gu X, Lipsitz SR, . Comparative effectiveness of minimally invasive vs open radical prostatectomy. JAMA. 2009;302(14):1557–1564.19826025
2 Wright JD. Robotic-Assisted Surgery: Balancing Evidence and Implementation. JAMA. 2017;318(16):1545–1547.29067404
3 Michels CTJ, Wijburg CJ, Leijte E, Witjes JA, Rovers MM, Grutters JPC. A cost-effectiveness modeling study of robot-assisted (RARC) versus open radical cystectomy (ORC) for bladder cancer to inform future research. European urology focus. 2018.
4 Childers CP, Maggard-Gibbons M. Estimation of the Acquisition and Operating Costs for Robotic Surgery. JAMA. 2018;320(8):835–836.30167686
5 Ramirez PT, Frumovitz M, Pareja R, . Minimally Invasive versus Abdominal Radical Hysterectomy for Cervical Cancer. N Engl J Med. 2018;379(20):1895–1904.30380365
6 Higgins JP AD, Gøtzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. BMJ. 2011:343:d5928.22008217
7 Sterne JA HM, Reeves BC, .. ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016:355:i4919.27733354
8 GRADE working group. 2014; http://www.gradeworkinggroup.org/. Accessed 04/26/2019.
9 Bochner BH, Sjoberg DD, Laudone VP. A randomized trial of robot-assisted laparoscopic radical cystectomy. New England journal of medicine. 2014;371(4):389–390.25054732
10 Bochner BH, Dalbagni G, Marzouk KH, . Randomized Trial Comparing Open Radical Cystectomy and Robot-assisted Laparoscopic Radical Cystectomy: Oncologic Outcomes. European urology. 2018;74(4):465–471.29784190
11 Khan MS, Gan C, Ahmed K, . A Single-centre Early Phase Randomised Controlled Three-arm Trial of Open, Robotic, and Laparoscopic Radical Cystectomy (CORAL). European urology. 2016;69(4):613–621.26272237
12 Messer JC, Punnen S, Fitzgerald J, Svatek R, Parekh DJ. Health-related quality of life from a prospective randomised clinical trial of robot-assisted laparoscopic vs open radical cystectomy. BJU international. 2014;114(6):896–902.24862633
13 Nix J, Smith A, Kurpad R, Nielsen ME, Wallen EM, Pruthi RS. Prospective randomized controlled trial of robotic versus open radical cystectomy for bladder cancer: perioperative and pathologic results. European urology. 2010;57(2):196–201.19853987
14 Parekh DJ, Reis IM, Castle EP, . Robot-assisted radical cystectomy versus open radical cystectomy in patients with bladder cancer (RAZOR): an open-label, randomised, phase 3, non-inferiority trial. Lancet (London, England). 2018;391(10139):2525–2536.
15 Cusano A, Haddock P, Jr., Jackson M, Staff I, Wagner J, Meraney A. A comparison of preliminary oncologic outcome and postoperative complications between patients undergoing either open or robotic radical cystectomy. International braz j urol : official journal of the Brazilian Society of Urology. 2016;42(4):663–670.
16 Gandaglia G, Karl A, Novara G, . Perioperative and oncologic outcomes of robot-assisted vs. open radical cystectomy in bladder cancer patients: A comparison of two high-volume referral centers. European journal of surgical oncology : the journal of the European Society of Surgical Oncology and the British Association of Surgical Oncology. 2016;42(11):1736–1743.
17 Hu JC, Chughtai B, O’Malley P, . Perioperative Outcomes, Health Care Costs, and Survival After Robotic-assisted Versus Open Radical Cystectomy: A National Comparative Effectiveness Study. European urology. 2016;70(1):195–202.27133087
18 Kim TH, Sung HH, Jeon HG, . Oncological Outcomes in Patients Treated with Radical Cystectomy for Bladder Cancer: Comparison Between Open, Laparoscopic, and Robot-Assisted Approaches. Journal of endourology. 2016;30(7):783–791.27055782
19 Nguyen DP, Al Hussein Al Awamlh B, Wu X, . Recurrence patterns after open and robot-assisted radical cystectomy for bladder cancer. European urology. 2015;68(3):399–405.25709026
20 Hanna N, Leow JJ, Sun M, . Comparative effectiveness of robot-assisted vs. open radical cystectomy. Urologic oncology. 2018;36(3):88.e81–88.e89.
21 Simone G, Tuderti G, Misuraca L, . Perioperative and mid-term oncologic outcomes of robotic assisted radical cystectomy with totally intracorporeal neobladder: Results of a propensity score matched comparison with open cohort from a single-centre series. European journal of surgical oncology : the journal of the European Society of Surgical Oncology and the British Association of Surgical Oncology. 2018;44(9):1432–1438.
22 Omar K, Nair R, Malde S, Thurairaja R, Dasgupta P, Khan M. Long term oncological outcomes following the randomised controlled cystectomy: open, robotic and laparoscopic (CORAL) trial. European urology, supplements Conference: 33rd annual european association of urology congress, EAU 2018 Denmark. 2018;17(2):e535.
23 Tan YG, Allen JCJ, Tay KJ, Lee LS. Intermediate oncological outcomes in a contemporary series of robotic and open cystectomies-a propensity score adjusted analysis. BJU International. 2019;123:41–42.
24 Ashrafi A, Hueber PA, Rajarubendra N, . Patterns of bladder cancer recurrence after open and robotic radical cystectomy. Canadian Urological Association Journal. 2018;12(6):S60.
25 Kukreja JB, Metcalfe MJ, Qiao W, Kamat AM, Dinney CPN, Navai N. Cost-Effectiveness of Robot-assisted Radical Cystectomy Using a Propensity-matched Cohort. European urology focus. 2018.
26 Martin AD, Nunez RN, Castle EP. Robot-assisted radical cystectomy versus open radical cystectomy: a complete cost analysis. Urology. 2011;77(3):621–625.21122900
27 Bansal SS, Dogra T, Smith PW, . Cost analysis of open radical cystectomy versus robot-assisted radical cystectomy. BJU international. 2018;121(3):437–444.28984408
28 Chang KD, Abdel Raheem A, Kim KH, . Functional and oncological outcomes of open, laparoscopic and robot-assisted partial nephrectomy: a multicentre comparative matched-pair analyses with a median of 5 years’ follow-up. BJU international. 2018;122(4):618–626.29645344
29 Gu L, Ma X, Wang B, . Laparoscopic vs robot-assisted partial nephrectomy for renal tumours of >4 cm: a propensity score-based analysis. BJU international. 2018;122(3):449–455.29750392
30 Oh JJ, Lee JK, Kim K, Byun SS, Lee SE, Hong SK. Comparison of the Width of Peritumoral Surgical Margin in Open and Robotic Partial Nephrectomy: A Propensity Score Matched Analysis. PLoS One. 2016;11(6):e0158027.27336438
31 Peyronnet B, Seisen T, Oger E, . Comparison of 1800 Robotic and Open Partial Nephrectomies for Renal Tumors. Annals of surgical oncology. 2016;23(13):4277–4283.27411552
32 Wang Y, Shao J, Ma X, Du Q, Gong H, Zhang X. Robotic and open partial nephrectomy for complex renal tumors: a matched-pair comparison with a long-term follow-up. World journal of urology. 2017;35(1):73–80.27194142
33 Kızılay F, Turna B, Apaydın E, Semerci B. Comparison of long-term outcomes of laparoscopic and robot-assisted laparoscopic partial nephrectomy. The Kaohsiung journal of medical sciences. 2019;35(4):238–243.30887679
34 Yu YD, Nguyen NH, Ryu HY, Hong SK, Byun SS, Lee S. Predictors of renal function after open and robot-assisted partial nephrectomy: A propensity score-matched study. International Journal of Urology. 2019;26(3):377–384.30582218
35 Mir SA, Cadeddu JA, Sleeper JP, Lotan Y. Cost comparison of robotic, laparoscopic, and open partial nephrectomy. Journal of endourology. 2011;25(3):447–453.21247335
36 Buse S, Hach CE, Klumpen P, . Cost-effectiveness analysis of robot-assisted vs. open partial nephrectomy. The international journal of medical robotics + computer assisted surgery : MRCAS. 2018;14(4):e1920.29806209
37 Kates M, Ball MW, Patel HD, Gorin MA, Pierorazio PM, Allaf ME. The financial impact of robotic technology for partial and radical nephrectomy. Journal of endourology. 2015;29(3):317–322.25167378
38 Mano R, Schulman A, Hakimi AA, . Cost comparison of open and robotic partial nephrectomy using a short postoperative pathway. Urology. 2015;85(3):596–603.25586478
39 Niegisch G, Nini A, Michalski R, . Comparison of 2-Year Oncological Outcome and Early Recurrence Patterns in Patients with Urothelial Bladder Carcinoma Treated with Open or Robot-Assisted Radical Cystectomy with an Extracorporeal Urinary Diversion. Urologia internationalis. 2018;101(2):224–231.30045033
40 Tan WS, Sridhar A, Ellis G, . Analysis of open and intracorporeal robotic assisted radical cystectomy shows no significant difference in recurrence patterns and oncological outcomes. Urologic oncology. 2016;34(6):257.e251–259.
41 Parekh DJ, Messer J, Fitzgerald J, Ercole B, Svatek R. Perioperative outcomes and oncologic efficacy from a pilot prospective randomized clinical trial of open versus robotic assisted radical cystectomy. The Journal of urology. 2013;189(2):474–479.23017529
42 Smith A, Nix JW, Nielsen ME, Wallen E, Pruthi R. Prospective randomized controlled trial of robotic versus open radical cystectomy for bladder cancer: median 3-year follow-up. Journal of clinical oncology. 2012;30(5 SUPPL. 1).