# Acknowledgments

This topic was developed in response to a nomination by William Gunnar, MD, for the purpose of understanding the potential benefits and costs or robot-assisted surgery. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Roberta Shanman, Jon Bergman, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Mark Wilson, MD
  National Director of Surgery (10NC2)
  Department of Veterans Affairs
- William Gunnar, MD
  Former National Director of Surgery (10NC2)
  Department of Veterans Affairs

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- John Gore, MD
  Associate Professor, Adjunct Associate Professor-Surgery
  University of Washington
- Jim C. Hu, MD
  Professor of Urology, Weill Cornell Medicine
  Director, LeFrak Center for Robotic Surgery
- Mark Jordan, MD
  Chief of Urology
  Department of Veterans Affairs, Long Beach
- John Leppert, MD
  Associate Professor of Urology, Stanford University
  Urologist at Palo Alto VA
- Joe Liao, MD
  Professor of Urology, Stanford University
  VA Robotic Surgeon
- Matthew Rettig, MD
  Medical Director, Prostate Cancer Program of the Institute of Urologic Oncology, UCLA
  Professor, Division of Hematology-Oncology and Department of Urology, UCLA
- Kevin Win, MD
  Staff Anesthesiology, Department of Veterans Affairs

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.