# Summary and Discussion

## Summary of Evidence by Key Question

### Key Question 1A What is the clinical-effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for cystectomy?

In general, estimated blood loss was less and OR time was longer in patients treated with robot-assisted cystectomy compared to open cystectomy. The evidence about lymph node sampling shows that in most studies, but not all, there is no difference between procedures. The few studies comparing robot-assisted cystectomy to laparoscopic cystectomy found no difference in intraoperative outcomes. RCTs and observational studies support a conclusion that there are not significant differences between robot-assisted and open cystectomy in major complications, genitourinary complications, or LOS. Data are too imprecise to draw any conclusions about differences or lack thereof between robot-assisted cystectomy and laparoscopic cystectomy.

### Key Question 1B What is the clinical-effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for partial nephrectomy?

The data comparing robot-assisted partial nephrectomy to other approaches are sparse and have underlying methodologic limitations. With this caveat, there is a consistent finding of lower estimated blood loss in patient treated with robot-assisted partial nephrectomy compared to laparoscopic and open approaches. There is also a signal that LOS is shorter and major complications are fewer with robot-assisted partial nephrectomy, but the evidence falls short of conclusive.

Additionally, it is important to note that for robotic partial nephrectomy cold ischemia cannot be performed. This may favor the open procedure when looking at long-term functional outcomes, but the data are sparse.

### Key Question 2A and 2B What is the cost effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for cystectomy and partial nephrectomy?

The cost effectiveness of robotic surgery for either partial nephrectomy or cystectomy is uncertain with different studies reaching different conclusions depending on how the fixed and variable costs of the robot were considered and how health outcomes (benefits or complications) were measured and valued. In any event, all cost-effectiveness data to date only consider short-term outcomes and do not include longer-term outcomes, including oncologic outcomes, that would likely significantly influence the cost/benefit ratio for any given approach.

## Limitations

### Publication Bias

We were not able to test for publication bias and can make no conclusions about its possible existence. However, we feel it is extremely unlikely that there exists a high-quality randomized trial of robotic surgery versus other surgical approaches that we did not identify, and has similarly escaped detection by all other experts in this field. There are probably a plentitude of observational experiences about robotic therapies, from individual institutions, that have never been published, and the published literature likely represents only a small fraction of what could be known using observational studies.

### Study Quality

The randomized trials of cystectomy were judged to be at low risk of bias for short-term outcomes, like intraoperative and postoperative outcomes. They were judged to be at moderate risk of bias for longer-term outcomes. Likewise, the observational studies were judged to be at moderate risk of bias (due to their non-random assignment of treatments) for short-term outcomes and high risk of bias for longer-term outcomes.

### Heterogeneity

Some outcomes had heterogeneous results across studies (such as operating room time for patients undergoing partial nephrectomy and changes in glomerular filtration rate) while many others were more similar, such as estimated blood loss and operating time for patients undergoing cystectomy. Additionally, some findings for one procedure, like less estimated blood loss in patients getting robot-assisted cystectomy as compared to open cystectomy, were not observed for the other procedure (no such consistent differences were seen between procedures for estimate blood loss for partial nephrectomy procedures). Some of these differences may be due to inherent distinctions between the procedures themselves (meaning the option of organ preservation for kidney procedures is not relevant for cystectomy cases) but may also be due to differences in study design and execution or differences in the experience of the surgical teams involved. These cannot be disentangled without better randomized data, particularly for patients undergoing partial nephrectomy.

### Applicability of Findings to the VA Population

No studies were specific to VA populations. The applicability of these results to VA populations may depend on both the similarity of the patients studied to VA patients and the experience of the surgical teams using the robot to VA surgical team experience. However, the benefits for robotic approach may still be realized despite patient-level differences (VA patient population has greater burden of comorbidities than the general population), which will need to be confirmed in future studies. Urology as a surgical field has widely adopted robotic surgery, so the experience will likely translate well into the VA setting.

### Research Gaps/Future Research

Two research gaps are apparent. The first is randomized data for patients undergoing partial nephrectomy, in terms of short-term outcomes. The second is high-quality evidence with adequate long-term follow-up and sufficient statistical power to assess cancer outcomes between the operative approaches for either cystectomy or partial nephrectomy. RCTs for these conditions, when they have been attempted, generally do not have long-term follow-up (only 2 of 5 RCTs reported 5-year data) and then the number of enrolled subjects is too small to have sufficient statistical power to detect clinically important differences. The LACC trial for cervical cancer enrolled hundreds of patient and had 4.4 years follow-up.^5^ In contrast, only 40 patients have been enrolled in RCTs with 5-year follow-up for either of these 2 procedures. One inherent difference noted in the observational studies for both cystectomy and partial nephrectomy is the lower follow-up rate and shorter time interval for the robotic groups – which makes comparisons limited. This is particularly important as newer evidence for some GYN cancers suggests possible worse cancer outcomes with the robotic approach. Despite what appears to better or equivalent technical outcomes for cystectomy and likely partial nephrectomy, acceptable cancer and functional outcomes need to be confirmed. Specifically, studies should assess the functional quality of life outcomes for the bladder cancer patients and the ongoing kidney function for the partial nephrectomy patients. Better-quality cost-effectiveness studies are warranted as well – which will add to the understanding of how to balance the clinical benefits with increased cost of the procedure and perhaps savings that better clinical outcomes afford (decreased blood loss, LOS).