# Results

We identified 3,877 potentially relevant citations, of which 556 were included at the abstract screening. From these, a total of 305 abstracts were excluded. Excluded abstracts were categorized as background/other (n=17), systematic review (n=58), wrong comparison (n=129), wrong procedure (n=40), no long-term outcomes (n=15), and review/editorial (n=46). This left 251 publications for full-text review, of which 209 publications were excluded for the following reasons: sample size <80 (n=84), intervention (n=3), comparison, (n=4), procedure (n=3), follow-up <1 year or unclear cystectomy (n=22), follow-up < 3 year or unclear nephrectomy (n=63), no clinical data (n=7), other (n=1), review/editorial (n=16), duplicate (n=4), and full text unavailable (n=2). A full list of excluded studies from the full-text review is included in Appendix H. A total of 42 publications were identified at full-text review as meeting initial inclusion criteria: cost-effectiveness analyses (n=4), cost-only studies (n=4), publications describing 5 cystectomy RCTs (n=16), cystectomy observational studies (n=11), and nephrectomy observational studies (n=7). See Figure 1 for literature flow. Descriptions of included publications are available in the Evidence Table (Appendix G).

## Description of the Evidence

For cystectomy, 5 studies were RCTs (of note, 2 publications on one study were used to abstract data for one trial, those being authored by Bochner and colleagues and published in 2014 and 2018). Of these, one was a multi-institutional study. These RCTs we judged as being low risk of bias for intraoperative, early postoperative outcomes, and long-term outcomes. The assigned risk of bias was inherent to the nature of surgical interventions (blinding of intervention and outcome reported not possible). There were 11 observational studies on cystectomy, including 3 multi-institutional studies. The quality of the observational studies was in general moderate to high risk of bias. Many used propensity modeling which helped balance the comparative arms for patient and tumor characteristics. However, the risk of bias was higher for the long-term outcomes as follow-up time was lower in the robotic study arms.

For partial nephrectomy, 7 observational studies were identified for nephrectomy and judged as having low risk of bias in measurement classification of interventions, low risk of bias due to missing data, and low risk of bias in measurement of outcomes. Bias due to deviations from intended interventions and bias in selection of the reported result were low to medium. Overall, these studies were most limited by confounding and selection bias and had high to moderate risk of bias.

Figure 1 Literature Flow Chart

## KEY QUESTION 1A – CYSTECTOMY What is the clinical effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for cystectomy?

We identified 16 publications that met the inclusion criteria.^9–24^ Five studies were randomized trials^9–14^; of note, 2 publications were from the same study, but data were abstracted from both^9,10^ and the remaining studies were observational. All studies compared robot-assisted cystectomy to open cystectomy, and 3 studies also compared it to laparoscopic surgery.^11,18,22^ One of the 5 RCTs was a multi-institutional study (15 institutions) and the studies varied in size from 40 to 302 subjects. Eleven studies were observational; of these only 3 were multi-institutional. They varied in size from 148 to 9561 subjects.

Figure 2 presents graphically the results for 3 intraoperative outcomes: estimated blood loss (EBL), lymph node sampling (LNS), and operating room (OR) time. In 4 RCTs, the estimated blood loss was less in patients treated with robot-assisted cystectomy compared to open cystectomy, and in 3 of these RCTs this was a statistically significant difference. In one RCT, the estimated blood loss was slightly less in patients treated with laparoscopic cystectomy that robot-assisted cystectomy, although this difference was not statistically significant. In 2 of 3 observational studies, estimated blood loss was statistically significantly less in patients treated with robot-assisted cystectomy than open cystectomy. In one observational study, estimated blood loss was not statistically significantly less in patients treated with laparoscopic cystectomy than with robot-assisted cystectomy. For the outcome of lymph node sampling, differences between procedures were in general small and/or not statistically significant. For the outcome of OR time, 4 of 5 RCTs and both observational studies found this was greater in patients treated with robot-assisted cystectomy compared to open cystectomy, although in 1 of these studies this difference was not statistically significant. The 1 RCT that compared robot-assisted cystectomy to laparoscopic cystectomy found OR time was shorter in the latter.

Figure 2 Bladder Cancer: Intraoperative Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted cystectomy and either open (green triangles) or laparoscopic (gold circles) approaches. Randomized trial data are on the left-hand side, observational study data are on the right-hand side.

Figure 3 presents graphically the results for 3 post-operative outcomes: major complications, genitourinary complications, and length of stay. All 5 RCTs and 3 of the 4 observational studies reported no statistically significant differences in major complications between patients treated with robot-assisted cystectomy compared to open cystectomy. Both RCTs and 1 observational study reported no statistically significant difference in genitourinary complications between patients treated with robot-assisted cystectomy and open cystectomy. All 5 RCTs and 3 of 5 observational studies reported no statistically significant differences in length of stay; in the 2 remaining studies 1 reported statistically significant longer LOS for patients treated with robot-assisted cystectomy and the other 1 reported statistically significantly shorter LOS for patients treated with open cystectomy. The 2 studies comparing robot-assisted cystectomy to laparoscopic cystectomy were inconclusive.

Figure 3 Bladder Cancer: Postoperative Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted cystectomy and either open (green triangles) or laparoscopic (gold circles) approaches. Randomized trial data are on the left-hand side, observational study data are on the right-hand side.

Figure 4 presents graphically the results for 4 functional or cancer-specific outcomes: Functional Assessment of Cancer Therapy (FACT), positive surgical margins, recurrence, and recurrence-free survival. With only a rare exception, no study reported statistically significant differences in any of these outcomes between patients treated with robot-assisted cystectomy and open cystectomy or laparoscopic cystectomy. However, the 95% confidence intervals of outcomes are very wide, and clinically important differences cannot be excluded.

In terms of the available data for assessing differences in long-term cancer outcomes for cystectomy studies, among the 5 RCTs there was variability in terms of lack of reporting on long-term (> 1 year) oncologic outcomes, small sample sizes, and 4 of 5 RCTs were from single institutions. Additionally, several studies commented on the fact that a significant number of patients who were approached for enrollment chose the robotic approach over entering the trial (5/55 for the Bochner et al study^10^; 35% for Khan et al^11^). For Khan and colleagues,^11^ oncologic outcomes were reported at only 12 months and sample sizes were small (20 for the robotic-treated group, 19 laparoscopic-treated patients, and 20 open-treated patients). For Messer and colleagues,^12^ oncologic outcomes were again reported at 12 months. For Bochner and colleagues,^10^ the authors commented that “study was not powered to assess oncologic outcomes.” The study by Nix and colleagues^13^ also had small sample sizes (21 in the robotic group and 20 in the open group) and oncologic outcomes were not reported. Parekh and colleagues^14^ did report oncologic outcomes at 24 months with sample size of over 100 in both the robotic and open groups. Of note, 10% and 12% of patients assigned to each group did not go on to have the assigned surgery. In summary, the sample size and follow-up data from RCTs limit our ability to properly assess the long-term oncologic outcomes for robotic cystectomy versus the comparator procedures. Only 2 RCTs reported 5-year outcomes, and between them they only included data on 40 robot-treated cases.

Figure 4 Bladder Cancer: Functional/Cancer Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted cystectomy and either open (green triangles) or laparoscopic (gold circles) approaches. Randomized trial data are on the left-hand side, observational study data are on the right-hand side.

Of note, all urinary diversions included in the RCTs were performed extracorporeally, which was standard of care when these trials were conceived. Moreover, also most of our included observational studies exclusively analyzed RARC with an extracorporeal urinary diversion, and the remaining observational studies did not stratify their results by an extra- or intra-corporeal technique. At present, data on oncological outcomes of RARC performed with an intracorporeal urinary diversion are limited. Having said that, RARC is increasingly performed intracorporeally.

### Summary of Findings

In general, estimated blood loss was less and OR time was longer in patients treated with robot-assisted cystectomy compared to open cystectomy. The evidence about lymph node sampling shows that in most studies, but not all, there is no difference between procedures. The few studies comparing robot-assisted cystectomy to laparoscopic cystectomy found no difference in intraoperative outcomes. RCTs and observational studies support a conclusion that there are not significant differences between robot-assisted and open cystectomy in major complications, genitourinary complications, or length of stay. Data are too imprecise to draw any conclusions about differences or lack thereof between robot-assisted cystectomy and laparoscopic cystectomy.

### Certainty of Evidence for Key Question 1A

We judged the certainty of evidence for the outcomes of lower EBL for robot-assisted cystectomy compared to open cystectomy as high. Data are consistent and come from both randomized trials and observational studies. We judged the certainty of evidence that there is no difference in lymph node sampling between these two procedures as low, due to inconsistency. We judged the certainty of evidence about longer OR time for robot-assisted cystectomy compared to open cystectomy as moderate. We judged the certainty of evidence for the 3 post-operative outcomes as moderate due to some imprecision. All comparisons of robot-assisted cystectomy to laparoscopic cystectomy were judged to be very low due to sparse data.

Table 1 Certainty of Evidence for Cystectomy Studies

Outcome | Study Limitations | Consistency | Directness | Precision | Certainty of Evidence
Intra-operative
Blood Loss; Robot < Open | RCT: Low; Observational studies: High | Consistent | Direct | Precise | High
Lymph Node Sampling; Robot = Open | RCT: Low; Observational studies: High | Inconsistent | Direct | Imprecise | Low
Operating Room Time; Robot > Open | RCT: Low; Observational studies: High | Consistent | Direct | Imprecise | Moderate
All comparisons to laparoscopic surgery | RCT: Low; Observational studies: High | N/A | Direct | Imprecise | Very Low
Post-operative
Major complications; Robot = Open | RCT: Low; Observational studies: High | Consistent | Direct | Imprecise | Moderate
Genitourinary complications; Robot = Open | RCT: Low; Observational studies: High | Consistent | Direct | Imprecise | Moderate
Length of Stay; Robot = Open | RCT: Low; Observational studies: High | Consistent | Direct | Imprecise | Moderate
All comparisons to laparoscopic surgery | RCT: Low; Observational studies: High | N/A | Direct | Imprecise | Very low
Functional/Cancer Outcomes
All outcomes | RCTs: Low to High depending on outcome; Observational studies: High | Inconsistent | Direct | Imprecise | Very low

## KEY QUESTION 1B – CYSTECTOMY What is the cost effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for cystectomy?

We identified 2 cost modeling studies for cystectomy.

The first was published in 2018.^25^ This study evaluated robotic versus open cystectomy. The authors used their own institution data to perform a propensity matched comparison of cases to identify the treatment effects for transfusions, complications, and readmissions. They also included their own institution data related to hospital costs. Stated hospitals costs included the acquisition and maintenance of the robot as well as “variable, technical, and professional fee costs”, although no further detail (including numbers) were provided for proprietary reasons. They did a literature search to provide ranges for the clinical outcomes and for health-related quality of life. They note that for some QOL measures, cystectomy-specific values were not available, and they assumed QOL was the same across all complications. They used a 90-day time horizon. Their results report that the robot was ~$17,000 more expensive over the 90-day time horizon but resulted in 0.32 additional QALYs over the open approach. Additional details are reportedly available in the supplement of the article, but was not available to us at the time of writing the report. An email has been sent to the authors in an attempt to obtain this data, but we did not receive a response.

The second was also published in 2018.^3^ This study evaluated robotic versus open cystectomy. They used primarily published data in the literature to ascertain rates of minor and major complications, OR time, and LOS. Some of these data were randomized (eg, the CORAL trial) but they included data from observational studies as well. They attempted to find QOL data but found none, and so presented their results in terms of cost per complication. They used primarily internal data from 2 Dutch hospitals for cost information. Costs included purchase ($2M, amortized over 7 years with 200 cases per operation) and maintenance costs for the robot ($150k/year) (total fixed costs of robot = $2254/case), the variable cost of robot instruments ($4,082/case), blood transfusions, OR “time” ($11/minute), anesthesia, professional fees for the urologist, hospital stay costs ($562/day), as well as costs of complications based on Clavien grade. They assumed an 11-day LOS for robot cases and 14 for open operations (likely much longer than contemporary US practice). They modeled 30- and 90-day time horizons. They found the extra cost of the robot to prevent one 30-day and one 90-day major complication was 62,582 euros (~$74k) and 37,007 euros (~$44k), respectively. Their sensitivity analyses showed very broad ranges for their estimates. For example, the risk of major complications in robot versus open surgery ranged from 29% in favor of the robot to 31% in favor of open operations. Cost information had a similarly wide confidence interval. In one analysis, they found that there were only 3 scenarios in which the robot was cost-saving – when OR time was less than 175 minutes, when LOS was less than or equal to 4 days, or if equipment costs could be reduced to 281 euros or less (their base case had OR time of 408 minutes, LOS of 11 days, and equipment costs of 3458 euros).

In addition to the above 2 studies, we identified 2 additional studies that assessed short-term costs of robot versus other approaches in cystectomy, but did not include (or make assumptions about) effectiveness, and thus were not classified as cost-effectiveness analyses. For cystectomy, the 2 published studies also reached different conclusions about short-term costs. In 1 small study (19 robotic cases and 14 open cases), differences in post-operative costs (LOS, transfusions, treatment of complications, and re-admissions) yielded a total cost of robotic procedures that was lower than open procedures (actual values not reported).^26^ In a companion modeling study, these authors reported that robotic cystectomy cases cost 16% lower than open cystectomy cases “when robot purchase and maintenance costs are eliminated from the model.” The other study used data from 68 open cystectomy cases and 221 robotic cystectomy cases to model the short-term costs of the 2 approaches.^27^ These authors found that robotic cases were almost 20% more expensive than open cases, and that this difference persisted (although diminished) even if the capital cost of the robot was “avoided via charitable donation”. This study concluded that “high ongoing equipment costs remain a large barrier” to the cost effectiveness of robotic procedures, but calculated that only modest improvement in quality adjusted life years (QALY) would be needed to make robotic surgery cost-effective using thresholds typical for the United Kingdom (about $30,000 per QALY).

### Summary of Findings

The 2 primary limitations are the underlying data behind the models and the short time horizon (which is similar to partial nephrectomy, which will be discussed to follow). The first study in cystectomy used a propensity matched internal data set and did not incorporate randomized data, despite its existence. The second does appear to have included some randomized data, but the method of pooling this data was not well-described and included both randomized and observational data. As a result, they found wide variation in their estimates on sensitivity analysis. They also did not include the latest, largest, RCT (RAZOR). While the cost analysis of one study was relatively granular and robust,^3^ the generalizability of their operative time and LOS measures to contemporary US practice is questionable. Further, the time horizon for both studies was 90 days – which is better than for either of the partial nephrectomy studies (discussed later), but still is too short to capture any meaningful oncologic outcomes.

### Certainty of Evidence for Key Question 1B

We judged the certainty of evidence for the outcome of cost effectiveness as very low, due to methods limitation, sparseness of data and inconsistent results.

## KEY QUESTION 2A – PARTIAL NEPHRECTOMY What is the clinical effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for partial nephrectomy?

Compared to cystectomy, the evidence regarding robot-assisted partial nephrectomy is less in amount and of less intrinsic methodologic rigor. There are no RCTs. Correspondingly, our ability to draw conclusions, and the certainty of evidence about those conclusions, is lessened.

We identified 7 observational studies for partial nephrectomy that met the inclusion criteria.^28–34^ One study compared robot-assisted nephrectomy to open partial nephrectomy and to laparoscopic partial nephrectomy.^28^ Three studies compared robot-assisted nephrectomy to open partial nephrectomy,^30,31,34^ and 3 studies^29,32,33^ compared it to laparoscopic partial nephrectomy. There were 3 studies that were multi-institutional, varying in size from 213 to 1800 patients. In general, the quality of the studies was moderate risk of bias for intraoperative and early postoperative outcomes. Long-term outcomes were more likely to have higher risk of bias because of loss of follow-up.

Figure 5 presents the results for 4 intra-operative outcomes: EBL, intraoperative complications, OR time, and warm ischemia time (WIT). Like cystectomy, a consistent finding in these studies is lower EBL in patients treated with robot-assisted partial nephrectomy compared to either open or laparoscopic approaches. Other outcomes were either not statistically different and/or close to the null. In 1 outlier study, the authors reported longer OR time for laparoscopic versus robotic surgery (241.9 vs 182.5 min; p=0.001).^28^ However, the authors comment that while this was a multi-institutional study, nearly all the robotic procedures were performed at 1 of the 4 institutions, which may in part account for this difference.

Figure 5 Kidney Cancer: Intraoperative Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted nephrectomy and either open (green triangles) or laparoscopic (gold circles) approaches. Randomized trial data are on the left hand-side, observational study data are on the right-hand side.

Figure 6 presents graphically the results for 2 post-operative outcomes: major complications and LOS. Four studies reporting LOS found this to be less for patients treated with robot-assisted partial nephrectomy compared to either open or laparoscopic approaches. In 1 study, there were no differences in LOS between robot-assisted and laparoscopic partial nephrectomy. In 3 of 4 studies, differences in the rate of major complications were lower for robot-assisted as compared to open partial nephrectomy. The remaining studies were either inconsistent and/or not statistically significantly different from the null value. The 95% confidence intervals were wide though, and a significant effect in the either direction cannot be excluded.

Figure 6 Kidney Cancer: Postoperative Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted nephrectomy and either open (green triangles) or laparoscopic (gold circles) approaches. Randomized trial data are on the left-hand side, observational study data are on the right-hand side.

Figure 7 presents graphically the results for 5 renal function or cancer-specific outcomes: positive surgical margins (PSM), glomerular filtration rate (GFR), cancer-specific survival, overall recurrence rate, and patients with chronic kidney disease (CKD) upstaging. With 3 exceptions, the studies reporting these outcomes found no statistically significant differences and/or results close to the null value of no difference. One exception was reported by Chang and colleagues.^28^ They found that the incidence of chronic kidney disease (CKD) upstaging was significantly lower in the robotic approach (20.5%) as compared with to laparoscopic approach (32%, p = 0.035) or open approach (33%, p = 0.038). Of note, this functional kidney outcome was not reported in 3 of the other observational studies. The other 2 exceptions were studies by Peyronnet and Yu that found statistically significant differences in overall recurrence rate favoring robot-assisted surgery.

Figure 7 Kidney Cancer: Functional/Cancer Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted nephrectomy and either open (green triangles) or laparoscopic (gold circles) approaches. Randomized trial data are on the left-hand side, observational study data are on the right-hand side.

The data for assessing differences in long-term outcomes for partial nephrectomy studies is limited to only observational studies (7) and no RCTs. The follow-up time within studies was variable and has the potential for bias due to differences in follow-up time between groups. Chang and colleagues^28^ did report 5-year follow-up for all 3 procedure arms, with median follow-up that was relatively similar: for robot-treated patients it was 60 (48–73) months; for laparoscopic-treated patients it was 60 (46–70) months; and for open-treated patients it was 64 (52–77) months (p = 0.331 for differences between groups). However, Gu and colleagues^29^ reported median follow-up of 20.1 months for the robotic group and 35 months for the laparoscopic group. Oh and colleagues^30^ reported a total median follow-up of 48.3 months for the full cohort, so potential differences in follow-up time between groups is not known. Peyronnet and colleagues^31^ reported 13-month median follow-up for robotic-treated patients as compared with 39 months for patients treated with an open approach. Wang et al,^32^ in contrast, reported median follow-up of 31.4 months for the robotic group and 16.5 months for the laparoscopic group. Studies by Kizilay and Yu reported no differences in cancer-specific survival. Six of these 7 observational studies used propensity matching which decreased the risk of bias in terms of confounding patient-level and tumor-characteristics; however, the variable follow-up may have introduced bias into the long-term cancer and functional kidney outcomes.

It is important to note that for robotic surgery (and laparoscopic surgery) there is the inability to provide cold ischemia during partial nephrectomy as compared to open partial nephrectomy. This may favor the open procedure when looking at long-term functional outcomes, which reiterates the need for large studies with adequate long-term follow-up.

### Summary of Findings

The data comparing robot-assisted partial nephrectomy to other approaches are sparse and have underlying methodologic limitations. With this caveat, there is a consistent finding of lower estimated blood loss in patient treated with robot-assisted partial nephrectomy compared to laparoscopic and open approaches. There is also a signal that LOS is shorter and major complications are fewer with robot-assisted partial nephrectomy, but the evidence falls short of conclusive.

### Certainty of Evidence for Key Question 2A

We judged the certainty of evidence for almost all outcomes as very low, due to methodologic limitations, sparseness of data, and either imprecision or inconsistency. The exceptions were the finding that estimated blood loss is less with robot-assisted procedures, and this conclusion draws added certainty from the parallel evidence on cystectomy which is consistent and comes from RCTs. We judged the certainty of the finding that EBL is less with robot-assisted surgery as moderate. The signal regarding LOS and fewer complications were considered to be low certainty, due to the observational nature of the data.

Table 2 Certainty of Evidence for Partial Nephrectomy Studies

Outcome | Study Limitations | Consistency | Directness | Precision | Certainty of Evidence
Intraoperative outcomes
Intraoperative complications; Robot = open/lap | High | Consistent | Direct | Imprecise | Low
Operating room time; Robot = open/lap | High | Inconsistent | Direct | Imprecise | Very low
Estimated blood loss; Robot < open/lap | High | Consistent | Direct | Imprecise | Moderate
Warm ischemia time; Robot = open/lap | High | Inconsistent | Direct | Imprecise | Very Low
Post-operative outcomes
Major complications; Robot < open | High | Consistent | Direct | Imprecise | Low
Major complications; Robot = lap | High | Consistent | Direct | Imprecise | Low
Length of stay; Robot < open/lap | High | Consistent | Direct | Imprecise | Low
Functional/Cancer Outcomes
All outcomes | High | Inconsistent | Direct | Imprecise | Very low

## KEY QUESTION 2B – PARTIAL NEPHRECTOMY What is the cost effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for partial nephrectomy?

We identified 2 cost modeling studies for partial nephrectomy.

The first was published in 2011.^35^ This study compared open, laparoscopic, and robotic partial nephrectomy. They used a healthcare sector perspective (specifically the perspective of the hospital) and looked at direct in-hospital costs. They pooled estimates from the literature to generate values for OR time and LOS and used internal cost data from a single institution related to robot, OR time ($12.90/minute), instruments, room and board ($508/night), lab, and pharmacy costs. Robot fixed costs included the purchase price ($1.5M) and annual maintenance contract ($150k). They amortized the purchase price over a 7-year time horizon and assumed 300 cases per year (average US utilization is probably closer to 200 cases/year).^4^ They also included 5 robotic instruments at $220/piece/case. They assumed complication rates were the same across all 3 approaches. Their results indicated that laparoscopic partial nephrectomy was the most cost-efficient with a mean direct cost of $10,311, with a cost advantage of $1,116 and $1,652 over open and robotic approaches, respectively. This cost advantage was mainly driven by lower LOS for laparoscopic operations that were lost for the robot because of equipment costs. All the data they rely on is observational and, with one exception, were published prior to 2010. The assumption that complication rates are similar between the approaches is untested in randomized data and there is observational evidence (cited in the study below) that this may not be the case.

The second study was published in 2018.^36^ This study compared open and robotic partial nephrectomy. They similarly used a healthcare sector perspective (that of the hospital) and looked at direct in-hospital costs. They relied on existing published data, specifically an analysis of the 2008-2010 National Inpatient Samples (NIS) to evaluate clinical outcomes and cost information from 2 single-site retrospective cohorts. The clinical outcomes they considered were intraoperative and postoperative complications and in-hospital death, all of which were lower in robotic surgery based on the NIS analysis. The underlying cost data excluded the purchase and maintenance of the robot, and there is a paucity of information regarding the cost accounting for the remaining cost inputs (eg, anesthesia, room and board).^6^ Their results indicated that the robotic approach “dominated” the open approach because of lower in hospital costs and better clinical outcomes.

In addition to the above 2 studies, we identified 2 additional studies that assessed short-term costs of robot versus other approaches in nephrectomy, but did not include (or make assumptions about) effectiveness, and thus were not classified as cost-effectiveness analyses. Two studies assessed nephrectomy and reached differing conclusions. One concluded that robotic partial nephrectomy had lower hospital charges than laparoscopic partial nephrectomy,^37^ while the other found that the immediate peri-operative costs of open partial nephrectomy was lower than robot partial nephrectomy.^38^ In addition to using different comparators (the first using laparoscopic, the second using open), the 2 analyses differed in 2 other important ways: the first study used hospital charges and did not consider the capital cost of the robot, whereas the second study used hospital costs and amortized the capital cost of the robot over 60 months. This last difference was decisive, in that amortized capital costs plus operating costs of the robot added $2,693 to the cost of each robotic partial nephrectomy for an analysis that concluded that robotic procedures were more expensive than open procedures by an overall mean cost of $2,539.

### Summary of Findings

The 2 primary limitations of these studies are (1) the data that inform their underlying model assumptions come from observational, often out-of-date, studies and (2) the very limited time horizon of their analysis (in-hospital only). Without randomized data, treatment effect estimates are prone to bias from underlying patient or time differences, and these biased treatment effects are often amplified when included in a modeling study. The fact that in one of the above studies the authors assumed no difference in complications, and in the other, the authors assumed large differences, illustrates the uncertainty. For costs, one study excluded the purchase and maintenance of the robot – despite it being the primary determinant of higher costs in the other study – and both studies only looked at in-hospital costs. The time horizon for therapy dedicated to oncology treatment should at least include readmissions and subsequent care dedicated to cancer management. Small differences in readmissions, reoperations, or oncologic recurrences would like lead to large differences in the average cost of a treatment approach, none of which were considered in these studies.

### Certainty of Evidence for Key Question 2B

We judged the certainty of evidence for the outcome of cost effectiveness as very low, due to methods limitations, sparseness of data, and inconsistent results.