# Methods

## Topic Development

This topic was developed in response to a nomination by Dr. Mark Wilson, National Director of Surgery (10NC2), and Dr. William Gunnar, former National Director of Surgery (10NC2). Key questions were then developed with input from the topic nominator, the ESP coordinating center, the review team, and the technical expert panel (TEP).

The Key Questions were:

KQ1A What is the clinical effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for cystectomy?
KQ1B What is the cost effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for cystectomy?
KQ2A What is the clinical effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for partial nephrectomy?
KQ2B What is the cost effectiveness of robotic-assisted surgery compared to open surgery or conventional laparoscopic surgery for partial nephrectomy?

The review was registered in PROSPERO: CRD 42019127413.

## Search Strategy

We conducted searches in PubMed from 1/1/2010-6/29/2019 and Cochrane (all databases) from 1/1/2010-6/29/2019. The search used a broad set of terms relating to “robotic surgical procedures” or “robotic-assisted”, “cystectomy” or “nephrectomy”, and “cost-effectiveness”. Prior to 2010, robotic procedures were not widely being performed and many surgeons were still in the so-called “learning curve”. As such, our technical expert panel considered evidence from studies published prior to the year 2010 to be insufficiently relevant to modern practice. See Appendix A for complete search strategy.

## Study Selection

Four team members working in pairs independently screened the titles of retrieved citations. For titles deemed relevant by at least 1 person, abstracts were then screened independently in duplicate by 5 team members working in pairs. All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by 2 independent team members, with any disagreements resolved through discussion. Studies were included at either the abstract or the full-text level if they were randomized control trials or observational studies comparing robotic surgery with either laparoscopic or open surgical approaches for either of the included surgical procedures. We also included publications of cost-effectiveness models that compared robotic surgery with laparoscopic or open surgical approaches. We included all RCTs regardless of outcomes studied or sample size. To be included, observational studies had to report long-term oncologic outcomes and include at least 80 operations. These thresholds were chosen such that the included studies accounted for at least 75% of the total available sample size.

## Data Abstraction

Data extraction was completed in duplicate. All discrepancies were resolved with full group discussion. We abstracted data on the following: study design, patient characteristics, sample size, tumor characteristics, intraoperative outcomes, postoperative outcomes (early), long-term functional outcomes (including kidney function) and cancer outcomes, duration of follow-up, and data needed for the Cochrane Risk of Bias tool or Cochrane Risk of Bias In Non-randomized Studies – of Interventions (ROBINS-I).

## Quality Assessment

Randomized controlled trials were assessed for quality (risk of bias) with the Cochrane Risk of Bias tool.^6^ This tool requires an assessment of whether a study is at high or low (or unknown) risk of bias in 7 domains: random sequence generation, allocation concealment, blinding of participants and personnel, blinding of outcome assessment, incomplete outcome data, selective outcome reporting, and other (See Appendix C for tool; Appendix E for table). We used the Risk of Bias In Non-randomized Studies – of Interventions (ROBINS-I) for observational studies.^7^ This tool requires an assessment of whether a study is at critical, serious, moderate, or low risk of bias (or no information) in 7 domains: confounding, selection bias, bias in measurement classification of interventions, bias due to deviations from intended interventions, bias due to missing data, bias in measurement of outcomes, and bias in selection of the reported result (see Appendix D for tool; Appendix F for table). Since observational studies are not required to have published an a priori protocol, we operationalized the last domain (bias in selection of the reported result) as requiring that studies report the most common variables.

## Data Synthesis

Because the randomized control trials were too heterogeneous, we did not conduct a meta-analysis of trials. The observational studies were too clinically heterogeneous to support meta-analysis; hence, our synthesis is narrative.

## Rating the Body of Evidence

We used the criteria of the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group.^8^ GRADE assessing the certainty of the evidence based of the assessment of the following domains: risk of bias, imprecision, inconsistency, indirectness, and publication bias. This results in categories as follows:

- High: We are very confident that the true effect lies close to that of the estimate of the effect.
- Moderate: We are moderately confident in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
- Low: Our confidence in the effect estimate is limited. The true effect may be substantially different from the estimate of the effect.
- Very low/Insufficient: We have very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.

## Peer Review

A draft version of the report was reviewed by technical experts and clinical leadership. Reviewer comments and our response are documented in Appendix B.