# Introduction

The robotic surgical platform was introduced in 1999, and by the end of 2017 over 3000 robotic platforms were installed throughout the United States.^4^ Urologic surgery was one of the first surgical disciplines to adopt the robotic approach, in part because open prostatectomy was a morbid procedure and traditional minimally invasive techniques (laparoscopy) were difficult to apply to this procedure.^1,2^ As of 2017, over 750,000 robotic procedures are performed each year in the United States including over 125,000 urologic robotic procedures.

Despite the rapid adoption of the approach, there is a growing body of literature questioning the utility of robotic surgery compared to laparoscopic and open surgery. For example, the recent ROLARR trial in rectal cancer surgery found no difference between robotic surgery and laparoscopic surgery for conversion rates, intraoperative and postoperative complications, functional outcomes, or mortality.^2^ Further, the Laparoscopic Approach to Cervical Cancer (LACC) trial published in 2018 compared minimally invasive surgery, including laparoscopic and robotic, to open surgery in early-stage cervical cancer and found worse survival in the minimally invasive group.^5^ This recently prompted the FDA to issue a warning stating that “The relative benefits and risks of surgery using robotically-assisted surgical devices compared to conventional surgical approaches in cancer treatment have not been established.” As a part of that statement, the FDA encouraged researchers to study robotic surgery, especially as it relates to long-term clinical and oncologic outcomes.

Further complicating the debate is the economics of the robotic platform. The robotic platform requires a significant upfront investment, an annual maintenance contract, and ongoing instrument purchases, not to mention staff and training costs, advertising, and infrastructure upgrade expenses. On the other hand, if the robotic platform can reduce length of stay, complications, readmissions, or improve oncologic outcomes, then these costs may be more than recuperated.

In light of recent evidence in other surgical disciplines questioning the utility of the robotic platform, it is important to re-visit the evidence surrounding the use of the robotic platform in urologic surgery, especially for long-term clinical and oncologic outcomes. And while the robotic approach has become the common approach to prostatectomy, there are other urologic procedures – namely partial nephrectomy and cystectomy – where the introduction of the robotic approach is still occurring and an evidence synthesis may be useful.

To help clinicians, patients, and policymakers make decisions about robotic and other surgical approaches in patients undergoing partial nephrectomy and cystectomy, we were asked to conduct a systematic review of benefits and cost effectiveness.