# APPENDIX H Citations for Excluded Publications

## Intervention (n=3)

1 Fraisse, G., Peri-operative and local control outcomes of robot-assisted partial nephrectomy vs percutaneous cryoablation for renal masses: comparison after matching on radiological stage and renal score. BJU Int, 2018.
2 Tanagho, Y.S., Renal cryoablation versus robot-assisted partial nephrectomy: Washington University long-term experience. J Endourol, 2013. 27(12): p. 1477–86.24283518
3 Weinberg, A.C., Utilization and perioperative complications of laparoscopic cryoablation vs robotic partial nephrectomy for localized renal tumors. Int Braz J Urol, 2015. 41(3): p. 473–85.26200540

## Comparison (n=4)

1 Ludwig, W.W., M.A. Gorin, and M.E. Allaf, Reducing the cost of robotic partial nephrectomy through innovative instrument use. European Urology, 2015. 67(3): p. 594–595.25465979
2 Philip, S., P. Hurley, and VSK. Mittal, Ureteric and Bladder Injuries with Laparoscopic and Robotic Surgery: A Community Teaching Hospital Experience. Am Surg, 2016. 82(4): p. E76–7.27097610
3 Pradere, B., Open partial nephrectomy vs robot-assisted partial nephrectomy for cystic renal masses: Impact of peroperative cystic spillage and oncological results. European Urology, Supplements, 2018. 17(2): p. e938–e940.
4 Salkini, M. and A. Lamoshi, Recurrence patterns of renal cell carcinoma after robotic partial nephrectomy. Journal of Endourology, 2018. 32: p. A223.

## Procedure (n=3)

1 Gershman, B., The Association of Robot-assisted Versus Pure Laparoscopic Radical Nephrectomy with Perioperative Outcomes and Hospital Costs. European Urology Focus, 2018.
2 Soria, F., Comparative Effectiveness in Perioperative Outcomes of Robotic versus Open Radical Cystectomy: Results from a Multicenter Contemporary Retrospective Cohort Study. European Urology Focus, 2018.
3 Tamhankar, A.S., Robot-assisted radical nephroureterectomy with extended template lymphadenectomy for upper tract urothelial carcinoma: An outcome analysis. Indian J Urol, 2018. 34(3): p. 212–218.30034133

## Follow up <1 year or unclear (cystectomy) (n=22)

1 Multidomain Quantitative Recovery Following Radical Cystectomy for Patients Within the Robot-assisted Radical Cystectomy with Intracorporeal Urinary Diversion Versus Open Radical Cystectomy Randomised Controlled Trial: the First 30 Patients. European urology, 2018. 74(4): p. 531–534.29793815
2 Real-World Impact of Minimally Invasive Versus Open Radical Cystectomy on Perioperative Outcomes and Spending. Urology, 2018.
3 Borza, T., No Differences in Population-based Readmissions After Open and Robotic-assisted Radical Cystectomy: Implications for Post-discharge Care. Urology, 2017. 104: p. 77–83.28267606
4 Flamiatos, J.F., Open versus robot-assisted radical cystectomy: 30-day perioperative comparison and predictors for cost-to-patient, complication, and readmission. J Robot Surg, 2018.
5 Ko, O.S., Rates and Predictors of Conversion to Open Surgery During Minimally Invasive Radical Cystectomy. J Endourol, 2018. 32(6): p. 488–494.29620960
6 Koie, T., The feasibility and effectiveness of robot-assisted radical cystectomy after neoadjuvant chemotherapy in patients with muscle-invasive bladder cancer. Jpn J Clin Oncol, 2017. 47(3): p. 252–256.27980085
7 Kukreja, J.B., A comparison of pathologic and intermediate term oncologic outcomes following open and robotic radical cystectomy. Journal of Clinical Oncology, 2019. 37.
8 Leow, J.J., Propensity-matched comparison of morbidity and costs of open and robot-assisted radical cystectomies: a contemporary population-based analysis in the United States. Eur Urol, 2014. 66(3): p. 569–76.24491306
9 Li, A.Y., Patient-Reported Convalescence and Quality of Life Recovery: A Comparison of Open and Robotic-Assisted Radical Cystectomy. Surg Innov, 2016. 23(6): p. 598–605.27354552
10 Mally, D., Oncological outcome of robotic-assisted radical cystectomies compared to open radial cystectomies. Oncology Research and Treatment, 2018. 41: p. 205.
11 Matulewicz, R.S., National comparison of oncologic quality indicators between open and robotic-assisted radical cystectomy. Urol Oncol, 2016. 34(10): p. 431.e9–431.e15.
12 Modi, P.K., Real-World Impact of Minimally Invasive Versus Open Radical Cystectomy on Perioperative Outcomes and Spending. Urology, 2019. 125: p. 86–91.30366043
13 Monn, M.F., National trends in the utilization of robotic-assisted radical cystectomy: an analysis using the Nationwide Inpatient Sample. Urol Oncol, 2014. 32(6): p. 785–90.24863014
14 Moschini, M., Propensity-score-matched comparison of soft tissue surgical margins status between open and robotic-assisted radical cystectomy. Urologic Oncology: Seminars and Original Investigations, 2019. 37(3): p. 179.e1–179.e7.
15 Nazzani, S., Comparison of Perioperative Outcomes Between Open and Robotic Radical Cystectomy: A Population-Based Analysis. J Endourol, 2018. 32(8): p. 701–709.29845866
16 Necchi, A., Robot-assisted Versus Open Radical Cystectomy in Patients Receiving Perioperative Chemotherapy for Muscle-invasive Bladder Cancer: The Oncologist’s Perspective from a Multicentre Study. Eur Urol Focus, 2017.
17 Pak, J.S., Utilization Trends and Short-term Outcomes of Robotic Versus Open Radical Cystectomy for Bladder Cancer. Urology, 2017. 103: p. 117–123.28189553
18 Sharma, P., Surgical control and margin status after robotic and open cystectomy in high-risk cases: Caution or equivalence? World J Urol, 2017. 35(4): p. 657–663.27495912
19 Soria, F., Robotic radical cystectomy is associated with shorter length of stay and less blood loss than open radical cystectomy: Results from a large multicenter retrospective cohort. Journal of Urology, 2018. 199(4): p. e812–e813.
20 Tan, W.S., Intracorporeal robot-assisted radical cystectomy, together with an enhanced recovery programme, improves postoperative outcomes by aggregating marginal gains. BJU Int, 2018. 121(4): p. 632–639.29124853
21 Taylor, B., Does robotic cystectomy achieve oncologic efficacy for locally advanced bladder cancer? Journal of Urology, 2018. 199(4): p. e533.
22 Yu, H.Y., Comparative analysis of outcomes and costs following open radical cystectomy versus robot-assisted laparoscopic radical cystectomy: results from the US Nationwide Inpatient Sample. Eur Urol, 2012. 61(6): p. 1239–44.22482778

## Follow up <3 years or unclear (partial nephrectomy) (n=63)

1 Alameddine, M., Trends in Utilization of Robotic and Open Partial Nephrectomy for Management of cT1 Renal Masses. Eur Urol Focus, 2018.
2 Anderson, J.E., Hospital costs and length of stay related to robot-assisted versus open radical and partial nephrectomy for kidney cancer in the USA. J Robot Surg, 2012. 6(1): p. 19–22.27637975
3 Anele, U., Robotic versus laparoscopic radical nephrectomy: A matched paired multicenter analysis (rosula group). Journal of Urology, 2018. 199(4): p. e787.
4 Arora, S., What is the hospital volume threshold to optimize inpatient complication rate after partial nephrectomy? Urol Oncol, 2018. 36(7): p. 339.e17–339.e23.
5 Autorino, R., Incidence and risk factors for 30-day readmission in patients undergoing nephrectomy procedures: a contemporary analysis of 5276 cases from the National Surgical Quality Improvement Program database. Urology, 2015. 85(4): p. 843–9.25681252
6 Ayangbesan, A., Surgical approach does not impact margin status following partial nephrectomy for large renal masses. J Endourol, 2018.
7 Banapour, P., Nephrometry score matched robotic vs laparoscopic vs open partial nephrectomy. J Robot Surg, 2018.
8 Bertolo, R., Robot-assisted partial nephrectomy for CT2 renal tumors: Perioperative, functional and oncological outcomes from a multicenter analysis (the rosula project). Journal of Urology, 2018. 199(4): p. e540.
9 Bertolo, R., Pure laparoscopic versus robot-assisted partial nephrectomy for ct1b renal tumors: A single tertiary center experience. Journal of Urology, 2018. 199(4): p. e544.
10 Bertolo, R.G., Perioperative, functional and oncological outcomes of robot-assisted partial nephrectomy for cT2 renal tumors: A multicenter analysis (The ROSULA project). European Urology, Supplements, 2018. 17(2): p. e1471–e1472.
11 Blair, B.M., Predicted versus observed 30-day perioperative outcomes using the ACS NSQIP surgical risk calculator in patients undergoing partial nephrectomy for renal cell carcinoma. Int Urol Nephrol, 2018. 50(7): p. 1249–1256.29868938
12 Borghesi, M., Open, laparoscopic and robot-assisted partial nephrectomy: Comparison of perioperative outcomes and trifecta rate achievement in a large, single-institution series. European Urology, Supplements, 2018. 17(2): p. e1468–e1469.
13 Camp, C., Short-term Outcomes and Costs Following Partial Nephrectomy in England: A Population-based Study. Eur Urol Focus, 2017.
14 Carneiro, A., Evolution from laparoscopic to robotic nephron sparing surgery: a high-volume laparoscopic center experience on achieving ‘trifecta’ outcomes. World J Urol, 2015. 33(12): p. 2039–44.25869814
15 Dagenais, J., Frozen Sections for Margins During Partial Nephrectomy Do Not Influence Recurrence Rates. J Endourol, 2018. 32(8): p. 759–764.29943659
16 Ellison, J.S., A matched comparison of perioperative outcomes of a single laparoscopic surgeon versus a multisurgeon robot-assisted cohort for partial nephrectomy. J Urol, 2012. 188(1): p. 45–50.22578725
17 Ficarra, VS, Tumor Contact Surface Area as predictor of postoperative complications and renal function in patients undergoing partial nephrectomy for renal tumors. BJU Int, 2018.
18 Ficarra, VS, A multicentre matched-pair analysis comparing robot-assisted versus open partial nephrectomy. BJU Int, 2014. 113(6): p. 936–41.24219227
19 Gadelmoula, M., Robot-assisted versus open partial nephrectomy in obese patients. Journal of Endourology, 2018. 32: p. A447–A448.
20 Gao, Y., Comparison of peri-operative and functional outcomes between robot-assisted and laparoscopic partial nephrectomy for renal tumors with a map score =3. Journal of Urology, 2018. 199(4): p. e543–e544.
21 Garisto, J., Robotic versus open partial nephrectomy for highly complex renal masses: Comparison of perioperative, functional, and oncological outcomes. Urol Oncol, 2018. 36(10): p. 471.e1–471.e9.
22 Ghani, K.R., Practice patterns and outcomes of open and minimally invasive partial nephrectomy since the introduction of robotic partial nephrectomy: results from the nationwide inpatient sample. J Urol, 2014. 191(4): p. 907–12.24184365
23 Hamilton, Z., Robotic vs open partial nephrectomy for patients with pre-existing chronic kidney disease. Journal of endourology. Conference: 34th world congress of endourology, WCE 2016. South africa. Conference start: 20161108. Conference end: 20161112, 2016. 30: p. A120.
24 Hamilton, Z.A., Comparison of functional outcomes of robotic and open partial nephrectomy in patients with pre-existing chronic kidney disease: a multicenter study. World J Urol, 2018. 36(8): p. 1255–1262.29532222
25 Han, K.S., Comparison of Hand-Assisted Laparoscopic vs Robot-Assisted Laparoscopic vs Open Partial Nephrectomy in Patients with T1 Renal Masses. J Endourol, 2017. 31(4): p. 374–379.25353326
26 Hanzly, M., Learning curves for robot-assisted and laparoscopic partial nephrectomy. J Endourol, 2015. 29(3): p. 297–303.25111313
27 Harke, N.N., Are there limits of robotic partial nephrectomy? TRIFECTA outcomes of open and robotic partial nephrectomy for completely endophytic renal tumors. J Surg Oncol, 2018. 118(1): p. 206–211.29878367
28 Hemal, S., Open vs robotic partial nephrectomy for renal masses with renal score >9: Comparison of perioperative and oncological outcomes. Journal of Endourology, 2018. 32: p. A440.
29 Hughes, D., Health resource use after robot-assisted surgery vs open and conventional laparoscopic techniques in oncology: analysis of English secondary care data for radical prostatectomy and partial nephrectomy. BJU Int, 2016. 117(6): p. 940–7.26696305
30 Jin, S.J., Comparison of postoperative pain between laparoscopic and robot-assisted partial nephrectomies for renal tumors: A propensity score matching analysis. Medicine (Baltimore), 2017. 96(29): p. e7581.28723795
31 Jin, S.J., Comparison of postoperative pain between laparoscopic and robot-assisted partial nephrectomies for renal tumors. Medicine (United States), 2017. 96(29).
32 Kara, O., Comparison of robot-assisted and open partial nephrectomy for completely endophytic renal tumours: a single centre experience. BJU Int, 2016. 118(6): p. 946–951.27477777
33 Khalifeh, A., Comparative outcomes and assessment of trifecta in 500 robotic and laparoscopic partial nephrectomy cases: a single surgeon experience. J Urol, 2013. 189(4): p. 1236–42.23079376
34 Khandwala, Y.S., Surgeon preference of surgical approach for partial nephrectomy in patients with baseline chronic kidney disease: a nationwide population-based analysis in the USA. Int Urol Nephrol, 2017. 49(11): p. 1921–1927.28852937
35 Kim, J.H., Perioperative and long-term renal functional outcomes of robotic versus laparoscopic partial nephrectomy: a multicenter matched-pair comparison. World J Urol, 2015. 33(10): p. 1579–84.25585500
36 Kim, J.K., Comparison of robotic and open partial nephrectomy for highly complex renal tumors (RENAL nephrometry score 10). PLoS ONE, 2019. 14(1).
37 Laydner, H., Single institutional cost analysis of 325 robotic, laparoscopic, and open partial nephrectomies. Urology, 2013. 81(3): p. 533–8.23295137
38 Lee, C., Comparison of Renal Function between Robot-Assisted and Open Partial Nephrectomy as Determined by Tc 99m-DTPA Renal Scintigraphy. J Korean Med Sci, 2016. 31(5): p. 743–9.27134496
39 Lee, S., Open versus robot-assisted partial nephrectomy: effect on clinical outcome. J Endourol, 2011. 25(7): p. 1181–5.21657825
40 Long, J.A., Robotic versus laparoscopic partial nephrectomy for complex tumors: comparison of perioperative outcomes. Eur Urol, 2012. 61(6): p. 1257–62.22464543
41 Luciani, L.G., Robotic-assisted partial nephrectomy provides better operative outcomes as compared to the laparoscopic and open approaches: results from a prospective cohort study. J Robot Surg, 2017. 11(3): p. 333–339.28000016
42 Malkoc, E., Robot-assisted approach improves surgical outcomes in obese patients undergoing partial nephrectomy. BJU Int, 2017. 119(2): p. 283–288.27699971
43 Mari, A., Predictive factors of overall and major postoperative complications after partial nephrectomy: Results from a multicenter prospective study (The RECORd 1 project). Eur J Surg Oncol, 2017. 43(4): p. 823–830.27876194
44 Masson-Lecomte, A., A prospective comparison of surgical and pathological outcomes obtained after robot-assisted or pure laparoscopic partial nephrectomy in moderate to complex renal tumours: results from a French multicentre collaborative study. BJU Int, 2013. 111(2): p. 256–63.23279002
45 Maurice, M.J., Optimum outcome achievement in partial nephrectomy for T1 renal masses: a contemporary analysis of open and robot-assisted cases. BJU Int, 2017. 120(4): p. 537–543.28437021
46 Minervini, A., The occurrence of intraoperative complications during partial nephrectomy has a significant impact on postoperative outcome: results from the RECORd1 project. Minerva Urol Nefrol, 2018.
47 Minervini, A., Open versus robotic-assisted partial nephrectomy: a multicenter comparison study of perioperative results and complications. World J Urol, 2014. 32(1): p. 287–93.23913095
48 Mullins, J.K., Comparative analysis of minimally invasive partial nephrectomy techniques in the treatment of localized renal tumors. Urology, 2012. 80(2): p. 316–21.22698464
49 Pak, J.S., Utilization trends and outcomes up to 3 months of open, laparoscopic, and robotic partial nephrectomy. J Robot Surg, 2017. 11(2): p. 223–229.27804062
50 Porpiglia, F., Partial Nephrectomy in Clinical T1b Renal Tumors: Multicenter Comparative Study of Open, Laparoscopic and Robot-assisted Approach (the RECORd Project). Urology, 2016. 89: p. 45–51.26743388
51 Ricciardulli, S., Evaluation of laparoscopic vs robotic partial nephrectomy using the margin, ischemia and complications score system: a retrospective single center analysis. Arch Ital Urol Androl, 2015. 87(1): p. 49–55.25847897
52 Sammon, J.D., Robot-assisted vs laparoscopic partial nephrectomy: utilization rates and perioperative outcomes. Int Braz J Urol, 2013. 39(3): p. 377–86.23849569
53 Simhan, J., Perioperative outcomes of robotic and open partial nephrectomy for moderately and highly complex renal lesions. J Urol, 2012. 187(6): p. 2000–4.22498208
54 Sprenkle, P.C., Comparison of open and minimally invasive partial nephrectomy for renal tumors 4-7 centimeters. Eur Urol, 2012. 61(3): p. 593–9.22154728
55 Tabayoyong, W., Variation in Surgical Margin Status by Surgical Approach among Patients Undergoing Partial Nephrectomy for Small Renal Masses. J Urol, 2015. 194(6): p. 1548–53.26094808
56 Takagi, T., A propensity score-matched comparison of surgical precision obtained by using volumetric analysis between robot-assisted laparoscopic and open partial nephrectomy for T1 renal cell carcinoma: a retrospective non-randomized observational study of initial outcomes. Int Urol Nephrol, 2016. 48(10): p. 1585–91.27262849
57 Wang, Y., Comparison of robot-assisted and laparoscopic partial nephrectomy for complex renal tumours with a RENAL nephrometry score >/=7: peri-operative and oncological outcomes. BJU Int, 2016. 117(1): p. 126–30.26132424
58 Wu, Z., Propensity-score matched analysis comparing robot-assisted with laparoscopic partial nephrectomy. BJU Int, 2015. 115(3): p. 437–45.24731125
59 Yerram, N., A comparison between robotic and open partial nephrectomy for multifocal tumors. Journal of Urology, 2018. 199(4): p. e539.
60 Yu, H.Y., Use, costs and comparative effectiveness of robotic assisted, laparoscopic and open urological surgery. J Urol, 2012. 187(4): p. 1392–8.22341274
61 Zargar, H., Assessing the effects of modality of surgery on postoperative weight loss in patients undergoing partial nephrectomy. World J Urol, 2017. 35(2): p. 271–275.27272313
62 Zargar, H., Trifecta and optimal perioperative outcomes of robotic and laparoscopic partial nephrectomy in surgical treatment of small renal masses: a multi-institutional study. BJU Int, 2015. 116(3): p. 407–14.25220543
63 Zhu, Z., Preoperative predictors of early death risk in bladder cancer patients treated with robot-assisted radical cystectomy. Cancer medicine, 2019.

## Sample Size <80 (n=84)

1 Abaza, R., Quality of lymphadenectomy is equivalent with robotic and open cystectomy using an extended template. J Urol, 2012. 187(4): p. 1200–4.22341295
2 Abdel Raheem, A., Robot-Assisted Partial Nephrectomy for Totally Endophytic Renal Tumors: Step by Step Standardized Surgical Technique and Long-Term Outcomes with a Median 59-Month Follow-Up. J Laparoendosc Adv Surg Tech A, 2018.
3 Aboumohamed, A.A., Health-related quality of life outcomes after robot-assisted and open radical cystectomy using a validated bladder-specific instrument: a multi-institutional study. Urology, 2014. 83(6): p. 1300–8.24746661
4 Ahdoot, M., Oncologic outcomes between open and robotic-assisted radical cystectomy: a propensity score matched analysis. World J Urol, 2014. 32(6): p. 1441–6.24469858
5 Alemozaffar, M., Comparing costs of robotic, laparoscopic, and open partial nephrectomy. J Endourol, 2013. 27(5): p. 560–5.23130756
6 Alimi, Q., Comparison of Short-Term Functional, Oncological, and Perioperative Outcomes Between Laparoscopic and Robotic Partial Nephrectomy Beyond the Learning Curve. J Laparoendosc Adv Surg Tech A, 2018. 28(9): p. 1047–1052.29664692
7 Atmaca, A.F., Open versus robotic radical cystectomy with intracorporeal Studer diversion. Jsls, 2015. 19(1): p. e2014.00193.
8 Bailey, G.C., Perioperative outcomes of robot-assisted laparoscopic partial cystectomy. J Robot Surg, 2018. 12(2): p. 223–228.28601954
9 Bak, D.J., Complications and oncologic outcomes following robot-assisted radical cystectomy: What is the real benefit? Investig Clin Urol, 2016. 57(4): p. 260–7.
10 Benoit, M., Laparoscopic Partial Nephrectomy After Selective Embolization and Robot-Assisted Partial Nephrectomy: A Comparison of Short-Term Oncological and Functional Outcomes. Clin Genitourin Cancer, 2018.
11 Borghesi, M., Retroperitoneal Robot-Assisted Versus Open Partial Nephrectomy for cT1 Renal Tumors: A Matched-Pair Comparison of Perioperative and Early Oncological Outcomes. Clin Genitourin Cancer, 2018. 16(2): p. e391–e396.29074284
12 Boylu, U., Comparison of surgical, functional, and oncological outcomes of open and robot-assisted partial nephrectomy. J Minim Access Surg, 2015. 11(1): p. 72–7.25598603
13 Caputo, P.A., Cryoablation versus Partial Nephrectomy for Clinical T1b Renal Tumors: A Matched Group Comparative Analysis. Eur Urol, 2017. 71(1): p. 111–117.27568064
14 Castle, S.M., Cost comparison of nephron-sparing treatments for cT1a renal masses. Urol Oncol, 2013. 31(7): p. 1327–32.22361086
15 Chehab, M., Percutaneous Cryoablation vs Partial Nephrectomy: Cost Comparison of T1a Tumors. J Endourol, 2016. 30(2): p. 170–6.26154481
16 Cho, C.L., Robot-assisted versus standard laparoscopic partial nephrectomy: comparison of perioperative outcomes from a single institution. Hong Kong Med J, 2011. 17(1): p. 33–8.
17 Choi, J.D., A comparison of surgical and functional outcomes of robot-assisted versus pure laparoscopic partial nephrectomy. Jsls, 2013. 17(2): p. 292–9.23925024
18 Chow, K., Early Australian experience of robotic-assisted radical cystectomies with intracorporeal urinary diversion versus open radical cystectomies. BJU international. Conference: 70th annual scientific meeting of the urological society of australia and new zealand. Australia, 2017. 119: p. 97.
19 Chow, K., Robotic-assisted radical cystectomy with intracorporeal urinary diversion versus open: early Australian experience. ANZ J Surg, 2018. 88(10): p. 1028–1032.29316106
20 Dar, T.I., Robotic-assisted versus laparoscopic partial nephrectomy: An experience with a novel technique of suturing. Saudi J Kidney Dis Transpl, 2015. 26(4): p. 684–91.26178538
21 Deboudt, C., Comparison of the morbidity and mortality of cystectomy and ileal conduit urinary diversion for neurogenic lower urinary tract dysfunction according to the approach: Laparotomy, laparoscopy or robotic. Int J Urol, 2016. 23(10): p. 848–853.27427278
22 DeLong, J.M., O. Shapiro, and A. Moinzadeh, Comparison of laparoscopic versus robotic assisted partial nephrectomy: one surgeon’s initial experience. Can J Urol, 2010. 17(3): p. 5207–12.20566016
23 Elsamra, S.E., Hand-assisted laparoscopic versus robot-assisted laparoscopic partial nephrectomy: comparison of short-term outcomes and cost. J Endourol, 2013. 27(2): p. 182–8.22891728
24 Emara, A.M., Robot-assisted partial nephrectomy vs laparoscopic cryoablation for the small renal mass: redefining the minimally invasive ‘gold standard’. BJU Int, 2014. 113(1): p. 92–9.24053473
25 Ferguson, J.E., 3rd, Cost analysis of robot-assisted laparoscopic versus hand-assisted laparoscopic partial nephrectomy. J Endourol, 2012. 26(8): p. 1030–7.22384936
26 Gondo, T., Robotic versus open radical cystectomy: prospective comparison of perioperative and pathologic outcomes in Japan. Jpn J Clin Oncol, 2012. 42(7): p. 625–31.22581913
27 Haber, G.P., Robotic versus laparoscopic partial nephrectomy: single-surgeon matched cohort study of 150 patients. Urology, 2010. 76(3): p. 754–8.20646744
28 Hillyer, S.P., Robotic versus laparoscopic partial nephrectomy for bilateral synchronous kidney tumors: single-institution comparative analysis. Urology, 2011. 78(4): p. 808–12.21855967
29 Hyams, E., A comparative cost analysis of robot-assisted versus traditional laparoscopic partial nephrectomy. J Endourol, 2012. 26(7): p. 843–7.22204599
30 Iwamoto, H., Robot-assisted radical cystectomy is a promising alternative to open surgery in the Japanese population with a high rate of octogenarians. Int J Clin Oncol, 2016. 21(4): p. 756–763.26792433
31 Jang, H.J., Comparison of perioperative outcomes of robotic versus laparoscopic partial nephrectomy for complex renal tumors (RENAL nephrometry score of 7 or higher). Korean J Urol, 2014. 55(12): p. 808–13.25512815
32 Jelley, C.R., Comparison of open and robotic nephron sparing surgery: a single centre experience. Journal of Clinical Urology, 2017. 10(1): p. 28–35.
33 Kader, A.K., Robot-assisted laparoscopic vs open radical cystectomy: comparison of complications and perioperative oncological outcomes in 200 patients. BJU Int, 2013. 112(4): p. E290–4.23815802
34 Khan, M.S., A dual-centre, cohort comparison of open, laparoscopic and robotic-assisted radical cystectomy. Int J Clin Pract, 2012. 66(7): p. 656–62.22507234
35 Kim, S.H., A propensity-matched comparison of perioperative complications and of chronic kidney disease between robot-assisted laparoscopic partial nephrectomy and radiofrequency ablative therapy. Asian J Surg, 2015. 38(3): p. 126–33.25458737
36 Kingo, P.S., Postoperative C-reactive protein concentration and clinical outcome: comparison of open cystectomy to robot-assisted laparoscopic cystectomy with extracorporeal or intracorporeal urinary diversion in a prospective study. Scand J Urol, 2017. 51(5): p. 381–387.28678652
37 Klaassen, Z., A Single Surgeon’s Experience with Open, Laparoscopic, and Robotic Partial Nephrectomy. Int Sch Res Notices, 2014. 2014: p. 430914.27379266
38 Knox, M.L., R. El-Galley, and J.E. Busby, Robotic versus open radical cystectomy: identification of patients who benefit from the robotic approach. J Endourol, 2013. 27(1): p. 40–4.22788707
39 Lee, N.G., A. Zampini, and I. Tuerk, Single surgeon’s experience with laparoscopic versus robotic partial nephrectomy: perioperative outcomes/complications and influence of tumor characteristics on choice of therapy. Can J Urol, 2012. 19(5): p. 6465–70.23040629
40 Lee, R., The economics of robotic cystectomy: cost comparison of open versus robotic cystectomy. BJU Int, 2011. 108(11): p. 1886–92.21501370
41 Lucas, S.M., A comparison of robotic, laparoscopic and open partial nephrectomy. Jsls, 2012. 16(4): p. 581–7.23484568
42 Maes, A.A., Comparison of robotic-assisted and open radical cystectomy in a community-based, non-tertiary health care setting. J Robot Surg, 2013. 7(4): p. 359–63.27001875
43 Malkoc, E., Robotic and open partial nephrectomy for localized renal tumors larger than 7 cm: a single-center experience. World J Urol, 2017. 35(5): p. 781–787.27663423
44 Martin, A.D., Robot-assisted radical cystectomy: intermediate survival results at a mean follow-up of 25 months. BJU Int, 2010. 105(12): p. 1706–9.19903170
45 Masson-Lecomte, A., A prospective comparison of the pathologic and surgical outcomes obtained after elective treatment of renal cell carcinoma by open or robot-assisted partial nephrectomy. Urol Oncol, 2013. 31(6): p. 924–9.21906969
46 Matsumoto, K., Robot-assisted laparoscopic radical cystectomy is a safe and effective procedure for patients with bladder cancer compared to laparoscopic and open surgery: Perioperative outcomes of a single-center experience. Asian J Surg, 2017.
47 Mearini, L., Margin and complication rates in clampless partial nephrectomy: a comparison of open, laparoscopic and robotic surgeries. J Robot Surg, 2016. 10(2): p. 135–44.27083923
48 Mellon, M.J., A comparison of pathologic outcomes of matched robotic and open partial nephrectomies. Int Urol Nephrol, 2013. 45(2): p. 381–5.23386247
49 Miyake, H., Partial nephrectomy for hilar tumors: comparison of conventional open and robot-assisted approaches. Int J Clin Oncol, 2015. 20(4): p. 808–13.25614490
50 Musch, M., Comparison of early postoperative morbidity after robot-assisted and open radical cystectomy: results of a prospective observational study. BJU Int, 2014. 113(1464-410X (Electronic)): p. 458–67.24053793
51 Nepple, K.G., Early oncologic outcomes of robotic vs open radical cystectomy for urothelial cancer. Urol Oncol, 2013. 31(6): p. 894–8.21803615
52 Ng, C.K., A comparison of postoperative complications in open versus robotic cystectomy. Eur Urol, 2010. 57(2): p. 274–81.19560255
53 Niegisch, G., P. Albers, and R. Rabenalt, Perioperative complications and oncological safety of robot-assisted (RARC) vs open radical cystectomy (ORC). Urol Oncol, 2014. 32(7): p. 966–74.25017695
54 Oh, J.J., Comparison of robotic and open partial nephrectomy: Single-surgeon matched cohort study. Can Urol Assoc J, 2014. 8(7–8): p. E471–5.25132891
55 Pai, A., Comparative outcomes of open and robotic-assisted radical cystectomy in an enhanced recovery programme era. Journal of Clinical Urology, 2014. 8(3): p. 215–221.
56 Pantelidou, M., Percutaneous Radiofrequency Ablation Versus Robotic-Assisted Partial Nephrectomy for the Treatment of Small Renal Cell Carcinoma. Cardiovasc Intervent Radiol, 2016. 39(11): p. 1595–1603.27435582
57 Panumatrassamee, K., Robotic versus laparoscopic partial nephrectomy for tumor in a solitary kidney: a single institution comparative analysis. Int J Urol, 2013. 20(5): p. 484–91.23126452
58 Panwar, P., Perioperative outcomes of minimally invasive versus open radical cystectomy: A single-center experience. Indian J Urol, 2018. 34(2): p. 115–121.29692504
59 Park, B.K., RFA versus robotic partial nephrectomy for T1a renal cell carcinoma: a propensity score-matched comparison of mid-term outcome. Eur Radiol, 2018. 28(7): p. 2979–2985.29426988
60 Pierorazio, P.M., Robotic-assisted versus traditional laparoscopic partial nephrectomy: comparison of outcomes and evaluation of learning curve. Urology, 2011. 78(4): p. 813–9.21802120
61 Ram, D., Is robot-assisted radical cystectomy superior to standard open radical cystectomy? An Indian perspective. J Minim Access Surg, 2018. 14(4): p. 298–303.29483372
62 Ramirez, D., Predicting complications in partial nephrectomy for T1a tumours: does approach matter? BJU Int, 2016. 118(6): p. 940–945.27410428
63 Richards, K.A., Robot assisted laparoscopic pelvic lymphadenectomy at the time of radical cystectomy rivals that of open surgery: single institution report. Urology, 2010. 76(6): p. 1400–4.20350755
64 Richards, K.A., Is robot-assisted radical cystectomy justified in the elderly? A comparison of robotic versus open radical cystectomy for bladder cancer in elderly >/=75 years old. J Endourol, 2012. 26(10): p. 1301–6.22582706
65 Richards, K.A., Is robot-assisted radical cystectomy justified in the elderly? acomparison of robotic versus open radical cystectomy for bladder cancer in elderly ≥75 years old. Journal of Endourology, 2012. 26(10): p. 1301–1306.22582706
66 Sagalovich, D., Trifecta Outcomes in Renal Hilar Tumors: A Comparison Between Robotic and Open Partial Nephrectomy. J Endourol, 2018. 32(9): p. 831–836.29984597
67 Seo, I.Y., Operative outcomes of robotic partial nephrectomy: a comparison with conventional laparoscopic partial nephrectomy. Korean J Urol, 2011. 52(4): p. 279–83.21556216
68 Simsek, A., Comparison of robotic and laparoscopic partial nephrectomy for small renal tumours. Arch Ital Urol Androl, 2017. 89(2): p. 93–96.28679176
69 Skjold Kingo, P., Perioperative Systemic Inflammatory Response following Robot-Assisted Laparoscopic Cystectomy vs Open Mini-Laparotomy Cystectomy: A Prospective Study. Urol Int, 2017. 99(4): p. 436–445.28668947
70 Smith, A., Cost analysis of robotic versus open radical cystectomy for bladder cancer. J Urol, 2010. 183(2): p. 505–9.20006882
71 Styn, N.R., Matched comparison of robotic-assisted and open radical cystectomy. Urology, 2012. 79(6): p. 1303–8.22516354
72 Sung, H.H., A comparison of early complications between open and robot-assisted radical cystectomy. J Endourol, 2012. 26(6): p. 670–5.22011001
73 Tachibana, H., Robot-assisted laparoscopic partial nephrectomy versus laparoscopic partial nephrectomy: A propensity score-matched comparative analysis of surgical outcomes and preserved renal parenchymal volume. Int J Urol, 2018. 25(4): p. 359–364.29397572
74 Takagi, T., Robot-assisted laparoscopic versus open partial nephrectomy in patients with chronic kidney disease: A propensity score-matched comparative analysis of surgical outcomes. Int J Urol, 2017. 24(7): p. 505–510.28503809
75 Tan, J.L., Comparison of perioperative, renal and oncologic outcomes in robotic-assisted versus open partial nephrectomy. ANZ J Surg, 2018. 88(3): p. E194–e199.28922687
76 Tanaka, K., Prospective study of robotic partial nephrectomy for renal cancer in Japan: Comparison with a historical control undergoing laparoscopic partial nephrectomy. Int J Urol, 2018. 25(5): p. 472–478.29671904
77 Vasdev, N., Robotic versus traditional laparoscopic partial nephrectomy: comparison of outcomes with a transition of techniques. J Robot Surg, 2014. 8(2): p. 157–61.27637525
78 Williams, S.B., Robotic partial nephrectomy versus laparoscopic partial nephrectomy: a single laparoscopic trained surgeon’s experience in the development of a robotic partial nephrectomy program. World J Urol, 2013. 31(4): p. 793–8.21274541
79 Winters, B.R., Preliminary Comparative Effectiveness of Robotic Versus Open Radical Cystectomy in Elderly Patients. J Endourol, 2016. 30(2): p. 212–7.26414964
80 Wu, Z., A propensity-score matched comparison of perioperative and early renal functional outcomes of robotic versus open partial nephrectomy. PLoS One, 2014. 9(4): p. e94195.24710511
81 Yang, C.M., Standardized analysis of laparoscopic and robotic-assisted partial nephrectomy complications with Clavien classification. J Chin Med Assoc, 2014. 77(12): p. 637–41.25441770
82 Yerram, N.K., Trifecta Outcomes in Multifocal Tumors: A Comparison Between Robotic and Open Partial Nephrectomy. J Endourol, 2018. 32(7): p. 615–620.29790375
83 Zargar, H., Comparison of perioperative outcomes of robot-assisted partial nephrectomy and open partial nephrectomy in patients with a solitary kidney. J Endourol, 2014. 28(10): p. 1224–30.24959704
84 Zhu, G., Comparison of perioperative outcomes of laparoscopic versus robotic assisted partial nephrectomy for patients with complex renal cell carcinoma: a single center initial experience from Northwest China. Journal of endourology. Conference: 35th world congress of endourology, WCE 2017. Canada, 2017. 31(Supplement 2): p. A315.

## No Clinical Data (n=7)

1 Bahler, C.D., Assessing Cost of Robotic Utilization in Partial Nephrectomy with Increasing Utilization. J Endourol, 2018. 32(8): p. 710–716.29943664
2 Bochner, B.H. and G. Dalbagni, Reply to Siebren Dijkstra and Carl J. Wijburg’s Letter to the Editor re: Bernard H. Bochner, Guido Dalbagni, Karim H. Marzouk, et al Randomized Trial Comparing Open Radical Cystectomy and Robot-assisted Laparoscopic Radical Cystectomy: Oncologic Outcomes. Eur Urol 2018;74:465–71. Can the Pattern of Cancer Recurrence Truly be Assigned to the Surgical Modality? European Urology, 2019. 75(5): p. e138–e139.30712972
3 Khetrapal, P., J.W.F. Catto, and J.D. Kelly, Robot-assisted versus open cystectomy in the RAZOR trial. The Lancet, 2019. 393(10172): p. 644–645.
4 Larcher, A., Robot-assisted versus open cystectomy in the RAZOR trial. The Lancet, 2019. 393(10172): p. 645.
5 Lubin, M.A., A. Tewari, and K.K. Badani, Robotic-assisted vs laparoscopic radical nephrectomy. JAMA - Journal of the American Medical Association, 2018. 319(11): p. 1165–1166.
6 Parekh, D.J. and VS Venkatramani, Robot-assisted versus open cystectomy in the RAZOR trial – Authors’ reply. The Lancet, 2019. 393(10172): p. 645–646.
7 Weiner, A.B., R.S. Matulewicz, and J.J. Meeks, Robotic-assisted vs laparoscopic radical nephrectomy. JAMA - Journal of the American Medical Association, 2018. 319(11): p. 1165.

## Review/Editorial (n=16)

1 Abeysiri, S. and T. Richards, Re: Dipen J. Parekh, Isidinha M. Reis, Erik P. Castle, et al Robot-assisted Radical Cystectomy Versus Open Radical Cystectomy in Patients with Bladder Cancer (RAZOR): An Open-label, Randomised, Phase 3, Non-inferiority Trial. Lancet 2018;391:2525-36: Blood Loss in Robot-assisted Radical Cystectomy: An Important Patient Benefit. Eur Urol, 2018(1873-7560 (Electronic)).
2 Choudhury, S.M., Oncological outcomes of robot-assisted radical cystectomy. BJU Int, 2011. 108(11): p. 1679–80.22044453
3 Desai, M.M. and I.S. Gill, The devil is in the details: Randomized trial of robotic versus open radical cystectomy. European Urology, 2015. 67(6): p. 1053–1055.25641689
4 Drake, R., Bladder cancer: Fewer complications after robotic cystectomy? Nature Reviews Urology, 2010. 7(6): p. 302.
5 Ficarra, VS, Robot-assisted vs traditional laparoscopic partial nephrectomy: The time for meta-analysis has not yet arrived. BJU International, 2013. 112(4): p. E334–E336.23879916
6 Ghavamian, R., Management of the small renal mass: What is the most reasonable option? Expert Review of Anticancer Therapy, 2011. 11(7): p. 977–980.21806319
7 Groves-Kirkby, N., Outcomes of robot-assisted radical cystectomy: Learning curves, margins and lymph node yield. Nature Reviews Urology, 2010. 7(9): p. 471.
8 Lau, C.S., R.H. Blackwell, and M.L. Quek, Radical cystectomy: open vs robotic approach. J Urol, 2015. 193(2): p. 400–2.25447101
9 Linares-Espinos, E. and R. Sanchez-Salas, Re: Robot-assisted Radical Cystectomy Versus Open Radical Cystectomy in Patients with Bladder Cancer (RAZOR): An Open-label, Randomised, Phase 3, Non-inferiority Trial. Eur Urol, 2018.
10 McClung, C. and A. Gorbonos, Ureteral reimplantation in adults: open versus robotic. J Urol, 2014. 192(4): p. 1023–5.25038466
11 Minervini, A., G. Siena, and M. Carini, Robotic-assisted partial nephrectomy: The next gold standard for the treatment of intracapsular renal tumors. Expert Review of Anticancer Therapy, 2011. 11(12): p. 1779–1782.22117144
12 Novara, G., VS Ficarra, and F. Zattoni, Is robot-assisted radical cystectomy the right way to reduce complications in patients undergoing radical cystectomy? European Urology, 2011. 59(2): p. 219–221.21144645
13 Resnick, M.J., Re: Association of Robotic-Assisted vs Laparoscopic Radical Nephrectomy with Perioperative Outcomes and Health Care Costs, 2003 to 2015. J Urol, 2018. 199(6): p. 1388–1389.
14 Salkini, M.W., A comparative study of open, laparoscopic and robotic partial nephrectomy in obese patients. Urol Ann, 2015. 7(2): p. 234–5.25835777
15 Seiler, R. and G.N. Thalmann, Robot-assisted versus open cystectomy. Lancet, 2018. 391(10139): p. 2479–2480.29976454
16 Warde, N., Surgery: Robot-assisted partial nephrectomy for large renal tumors. Nature Reviews Urology, 2010. 7(3): p. 120.

## Other (n=1)

1 Patil, M.B. and I.S. Gill, Zero-ischaemia robotic and laparoscopic partial nephrectomy (PN). BJU Int, 2011. 108(5): p. 780–92.21854529

## Duplicate (n=4)

1 Abeysiri, S. and T. Richards, Re: Dipen J. Parekh, Isidinha M. Reis, Erik P. Castle, et al Robot-assisted Radical Cystectomy Versus Open Radical Cystectomy in Patients with Bladder Cancer (RAZOR): An Open-label, Randomised, Phase 3, Non-inferiority Trial. Lancet 2018;391:2525–36: Blood Loss in Robot-assisted Radical Cystectomy: An Important Patient Benefit. European Urology, 2019. 75(2): p. e36.30268660
2 Buse, S., Cost-effectiveness of robot-assisted partial nephrectomy for the prevention of perioperative complications. World J Urol, 2016. 34(8): p. 1131–7.26659354
3 Tan, W.S., Oncological outcomes following intracorporeal robotic cystectomy versus open radical cystectomy: an analysis of 184 patients. BJU international. Conference: 71st annual scientific meeting of the british association of urological surgeons, BAUS 2015. United kingdom, 2015. 115: p. 13.
4 Messer, J., Health related quality of life from a prospective randomized clinical trial of robotic assisted laparoscopic versus open radical cystectomy. Journal of urology., 2014. 191(4 SUPPL. 1): p. e145–e146.

## Unavailable (n=2)

1 Kidney cancer: Single-surgeon robotic versus laparoscopic nephrectomy. Nature Reviews Urology, 2012.
2 Cao, D., Re: Comparison of Surgical Outcomes Between Resection and Enucleation in Robot-Assisted Laparoscopic Partial Nephrectomy for Renal Tumors According to the Surface-Intermediate-Base Margin Score: A Propensity Score-Matched Study (From: Takagi T, Kondo T, Tachibana H, et al J Endourol 2017;31:756-761). J Endourol, 2018. 32(4): p. 360–361.29113493