# APPENDIX G Evidence Tables

## Cystectomy RCT

## Cystectomy Observational Studies

### Partial Nephrectomy Observational Studies