# APPENDIX F Quality Assessment for Included Observational Studies

## Cystectomy^*^

| Confounding | Selection bias | Bias in measurement classification of interventions | Bias due to deviations from intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of the reported result
Tan 2019^23^ | Moderate: propensity matched; Severe: sig differences in gender, urinary diversion, disease characteristics | Low: consecutive series, all pts analyzed | Low | Low | Low | Low | Low
Ashrafi 2018^24^ | Severe: not propensity matched, adjusted for demographics | Low: consecutive series | Low | Low | Low | Low | Low
Niegisch 2018^39^ | Serious: small sample size, no propensity/multivariate; Moderate: only 2 year f/u | Low Stage matching | Low | Low | Moderate: pts excluded for short f/u | | Low
Simone 2018^21^ | Moderate: propensity matching; Low: time | Low | Low | Low | Low | Low: short-term (30d) outcomes; Low: long-term (4yr) outcomes; Moderate: efficacy | Low
Hanna 2017^20^ | Severe: patients; Low: time | Moderate | Moderate | Low | Moderate | Low: short-term (30d) outcomes; Moderate: long-term (2yr) outcomes; Low: efficacy | Moderate
Gandaglia 2016^16^ | Moderate: patients (neoadj); Low: time | Moderate: difference in stage | Low | Low | Moderate | Low: short-term outcomes; Low: long-term (5yr) outcomes; Low: Efficacy | Low
Hu 2016^17^ | Serious: patients (propensity matching); Low: time | Moderate | Moderate | Low | Low: outcomes; No info: efficacy | Low: short-term outcomes; Low: long-term (5yr) outcomes; Serious: efficacy | Moderate
Cusano 2016^15^ | Serious: patients; Low: time | Serious | Low | Low | Low | Low: short-term outcomes; Serious: long-term (<<2yr) outcomes; Moderate: efficacy (only PSM) | Low
Kim 2016^18^ | Moderate: patients age; Low: time | Low | Low | Low | Low | Low: short-term outcomes; Low: long-term (4yr) outcomes; Low: efficacy | Low
Tan 2016^40^ | Moderate: different pt populations; propensity matching; Severe: time (f/u for robot short) | Moderate: learning curve; robot instituted later | Low | Low | Low | Severe: Short-term outcomes, only margins; Moderate: long-term outcomes (only 2 yr); Moderate: Efficacy, margins and LNs | Low
Nguyen 2015^19^ | Moderate: patient age; Low: time | Moderate: difference in clinical stage | Low | Low | Low | Low: short-term outcomes; Moderate: long-term (2yr) outcomes; Low: efficacy | Low

* All 9 observational studies for cystectomy were most concerning for confounding due to the retrospective nature of the studies, and low in bias due to intervention deviation. Cusano et al and Nieglsch had a risk of serious confounding due to lack of propensity matching or multivariate analysis. Nieglsch also had small sample size for both arms. Hanna et al and Hu et al used large administrative datasets from NCDB (National Cancer Data Base) [Hanna] and SEER (Surveillance, Epidemiology, and End Results Program) respectively, making the studies prone to lack of standardization of surgical techniques, entering errors, misclassification, and missing observation across multiple centers. Thus both studies had seriousness for confounding bias; moderation in selection bias, bias in measurement classification, missing data bias, and reporting bias. Except for these 2 studies (due to adopting large administrative datasets and Niegisch et al due to large amount of excluding patients with less than 1 year follow-up), missing data bias was low among all the studies. Reporting bias was deemed to be low among all studies except Hanna et al and Hu et al as mentioned above. Cusano et al has serious selection bias due to lack of patient exclusion criteria. Gandaglia et al, Nguyen et al, and Tan et al have moderate selection bias due to prominent difference in clinical stages between arms as well as default operation of choice based on timeline of the study. Tan et al and Nieglsch et al had serious bias in short-term outcome measurement given only having PSM (positive surgical margin) results and lack of perioperative and short-term outcome results. All have moderate to serious long-term outcome bias due to short follow-up time (equal or less than 2 years), except Simone et al, Gandaglia et al, Hu et al, and Kim et al. Efficacy outcome is measured by PSM, amount of removed lymph node as well as perioperative results. The bias in efficacy outcome in Hu et al is considered to be serious as only the percentage of more than 10 lymph node removed was reported.

## Partial Nephrectomy

| Confounding | Selection bias | Bias in measurement classification of interventions | Bias due to deviations from intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of the reported result
Kizilay 2019^33^ | Moderate: propensity matched; Severe: sig differences in tumor laterality + location (RAPN - complex tumors); intraop technique and learning curve not accounted for | Severe: not consecutive series… unclear how many pts were excluded | Low | Low | Low | Low | Low
Yu 2019^34^ | Moderate: propensity matched; Severe: sig age, BMI, baseline eGFR, and tumor volume differences | Moderate: many pts excluded | Low | Low: conversions excluded | Moderate: missing data excluded (not clear how many) | Low | Low
Chang 2018^28^ | Moderate | Serious | Low | Low | Low | Low | Low
Gu 2018^29^ | Moderate | Serious | Low | Low | Low | Low | Low
Oh 2016^30^ | Moderate | Serious | Low | Moderate | Low | Low | Moderate
Peyronnet 2016^31^ | Serious | Low | Low | Moderate | Low | Low | Moderate
Wang 2015^32^ | Serious | Serious | Low | Moderate | Low | Low | Low