# APPENDIX E Quality Assessment for Included RCT Studies

Author, year | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessment | Incomplete outcome data | Selective reporting | Other sources of bias
Parekh, 2018^14^ | ○ | ● | ● | ●^*^ | ○ | ○ | ○
Bochner, 2018^10^ | ○ | ○ | ● | ●^*^ | ○ | ○ | ○
Khan, 2016^11^ | ○ | ○ | ● | ●^*^ | ○ | ○ | ○
Messer, 2014^12^ | ○ | ● | ● | ●^*^ | ○ | ○ | ●QOL
Nix, 2010^13^ | ● | ● | ● | ●^*^ | ○ | ○ | ○

○ = low risk of bias ● = risk of bias ⯋ = unknown

* low risk of bias for primary outcomes (all-cause mortality and amputation-free survival, but high risk of bias for secondary outcome