# APPENDIX B Peer Reviewer Comments and Responses

Comment | Response
Consider this study: J Urology 2019;201:715-720. Sathianathen et al. Robotic assisted radical cystectomy vs open radical cystectomy: Systematic Review and Meta-analysis | Thank you for pointing this out. This study analyzed the same 5 RCTs that have been included also in our report and, therefore, its results and conclusions are consistent with ours (with RARC presenting a decreased need for perioperative blood transfusion, but a longer operative time; there was no difference in disease progression, major complications or QOL).
Why did the authors choose 2010 as a start date? Understanding that the robotic platforms were introduced in 2005, and recognizing that the early literature from this period through 2010 is most likely low quality and high risk of bias, an explanation should be given for the date selection. | We selected 1/1/2010 search start date was chosen based on input from our TEP. After 2010 robotic-assisted procedures became more common and the studies published earlier often reflected learning curves. Thus evidence from studies published from prior to the year 2010 were determined by our TEP to be insufficiently relevant to modern practice. We have added this to the methods section.
The evidence likely also derives mostly from academic centers and centers of excellence and it is unclear if the mostly short-term results from these included studies would be generalizable to a broader population of urologic surgeons and VA settings. | The expense of the robotic platforms has limited broad uptake in community hospitals, and the bulk of the literature represents academic centers. However, as new robotic companies are emerging, community and VA hospitals may incorporate more robots. The training required to use the robot is structured and extensive, as such it is likely that non-academic surgeons will perform as a high quality level and results from our study will apply well. The contention is that centers with experience with the robotic platform can perform cystectomy and partial nephrectomy without compromising perioperative outcomes as well as oncologic outcomes. We attempted to ensure a high level of reliability between data by utilizing literature with large volume as well as recent publications such that it would not necessarily be generalizable to all urologic surgeons but potentially those who have overcome their learning curve and have adequate volume in their practice. Furthermore, a fair number of VA centers are high volume robotic centers currently. Our local VA is actually getting a second robot because of demand. We have a paragraph (page 26) that addresses the possible lack of generalizability of our findings to VA patients (page 36).
Line 20, this is a fragment: “over 125,000 procedures in 2017.” | Thank you for pointing this out, this has been corrected.
Line 43, “On 40 patients have been enrolled in RCTs with 5 year follow-up for either of these two procedures.” Should be “Only”. | Thank you for pointing this out, this has been corrected.
Line 48/49: “Robotic-assisted surgery for cystectomy and partial nephrectomy has a few documented short benefits” should be “short-term benefits”. | Thank you for pointing this out, this has been corrected.
Line 11 of the Evidence Report should be, “Urologic surgery was one of the first surgical disciplines to adopt robotic surgery”. | Thank you for pointing this out, this has been corrected.
Line 12 of Key Question 1a should have a semi-colon: “Five studies were randomized trials; of note, two publications were from the same study, but data were abstracted from both, and the remaining studies were observational.” | Thank you for pointing this out, this has been corrected.
Line 16 page 21 has an excess comma: “Additionally, several studies commented on the fact that a significant number of patients who were approached for enrollment, chose…” the comma before chose shouldn’t be there. | Thank you for pointing this out, this has been corrected.
This is an excellent and thorough review reviewing the literature evaluating the outcomes and cost effectiveness of minimally invasive techniques for radical cystectomy and partial nephrectomy. The authors have provided a comprehensive analysis of the published literature. The overall conclusions trending towards less blood loss for both RARC and RPN are well founded and generally accepted in the urologic literature. However, in more contemporary series, there is also a trend towards lower LOS favoring RARC. this is not reflected in the current review, largely because of the inclusion of1 observational study from Korea (Kim et al, J Endo 2016;30:783-791) which had a very high length of stay for both ORC (22 days) as well as RARC (28 days) which far exceeds what most US centers experience. Most of the RCTs of robotic vs open cystectomy show avg LOS in the 7-10 day range so the Korean study does not represent current practice. Whether this is because of not using an ERAS regimen or other factors relating to hospital practices in Korea cannot be ascertained. | We agree with the reviewer’s assessment that the study by Kim and colleagues is an outlier. However, the remaining studies show no statistically significant differences between approaches, so that we are unable to reach a conclusion that LOS is shorter with robot-assisted surgery.
Figures: it would be helpful to define abbreviations shown in the graphs also in the figure legends, not just the body of the manuscript. Also, including the numbers of patients in each study should be shown to give the data better context | Thank you for pointing this out, this has been corrected.
Figure 3: Although the LOS is shown for the Kim study, the LOS data is not included in the summary for this study (Appendix G p 56) | Thank you for pointing this out, this has been corrected.
The cost effectiveness data for cystectomy from the second paper from Europe (Ref #3) may not be directly comparable to costs in the US. | This is a valid consideration. However, a strength of cost-effectiveness analyses is that the relative difference within each study is reported. As such, we believe the finding of relative differences for this study are relevant as well to non-European based work.
Outcomes for RARC should be stratified according to whether the urinary diversion is done intracorporeally vs extracorporeally. Most of the RCTs do not make this distinction since the data is relatively sparse, however as more surgeons are performing intracorporeal diversion, it might be expected to change postoperative outcomes (? less ileus, ) and potentially LOS and cost. The authors should include this as a possibility to consider even though the existing literature does not. | All urinary diversions included in the RCTs were performed extracorporeally, which was standard of care when these trials were conceived. Moreover, also most of our included observational studies exclusively analyzed RARC with an extracorporeal urinary diversion, and the remaining observational studies didn’t stratify their results by an extra- or intra-corporeal technique. At present, data on oncological outcomes of RARC performed with an intracorporeal urinary diversion are limited. Having said that, RARC is increasingly performed intracorporeally, and we agree that future trials/studies should take this into consideration. We have added this comment to our limitations paragraph in the Discussion.
Key question 2A, p26. Last sentence comparing lap to robotic OR times for partial nephrectomy may be becoming moot since most MIS partial nephrectomies are now being done robotically. | Yes, we agree that the majority of partial nephrectomy cases are being performed robotically. However, our TEP believed it was still important to provide the evidence for open versus robotic and laparoscopic versus robotic, especially with the currently climate of robotic surgery oncology outcomes being questioned for other cancer types such as gynecologic surgery.
P 36 under “Heterogeneity”. The statement regarding “clamping the arterial supply of the kidney vs inability to do so for the bladder” should be deleted or modified since it is not relevant. There is no organ preservation attempted when performing RC. | Thank you. This was corrected.
One final point that is rarely discussed by the robotic surgeons is the inability to provide cold ischemia during MIS partial nephrectomy vs open partial nephrectomy. This may favor the open procedure when looking at long term functional outcomes. | Thank you for your comment. This important point addressing the difference in technique has been added to the Summary.

Of note, some minor improvements were made to language and presentation throughout the report. None of these changes were substantive.

As part of the revision process, we performed an update search, which resulted in 4 new included observational studies, 2 about cystectomy and 2 about partial nephrectomy. The inclusion of these new studies did not change any of the conclusions from the draft report.