# APPENDIX A Search Strategies

## Database Searched & Time Period Covered

PubMed – 1/1/2010-6/29/2019

## Language

English

## Search Strategy #1

“Similar Article” searches on the following 2 articles:

Systematic review and meta-analysis of randomised trials of perioperative outcomes comparing robot-assisted versus open radical cystectomy.

Shen Z1, Sun Z2.

BMC Urol. 2016 Sep 23;16(1):59.

Robotic versus open partial nephrectomy: a systematic review and meta-analysis.

Wu Z1, Li M2, Liu B1, Cai C3, Ye H1, Lv C1, Yang Q1, Sheng J2, Song S1, Qu L1, Xiao L1, Sun Y1, Wang L1.

PLoS One. 2014 Apr 16;9(4):e94878. doi: 10.1371/journal.pone.0094878. eCollection 2014.

## Search Strategy #2

Robotic Surgical Procedures"[Mesh] OR robotics[mh] OR robot-assisted OR robot*[tiab] OR robot*[ot]

AND

nephrectom* OR cystectom* OR nephrectomy[mh] OR ureter OR ureteral OR ureters

NOT

editorial[pt] OR editorial[ti] OR letter[pt] OR letter[ti] OR comment[pt] OR comment[ti]

====================================================================

## Database Searched & Time Period Covered

Embase – 1/1/2010-6/29/2019

## Language

English

## Search Strategy

‘robot assisted surgery’/exp OR ‘robot assisted surgery’ OR ‘robot assisted’ OR robot*

AND

‘cystectomy’/exp OR ‘cystectomy’ OR ‘nephrectomy’/exp OR ‘nephrectomy’ OR ‘ureter’/exp OR ureter OR ‘ureters’/exp OR ureters OR ureteral

AND

HUMAN

====================================================================

## Database Searched & Time Period Covered

Cochrane – All databases – 1/1/2010-6/29/2019

## Language

English

## Search Strategy

MeSH descriptor: [Robotic Surgical Procedures] explode all trees OR MeSH descriptor: [Robotics] explode all trees OR (robotic-assisted OR robot*):ti,ab,kw

AND

MeSH descriptor: [Nephrectomy] explode all trees OR MeSH descriptor: [Cystectomy] explode all trees OR MeSH descriptor: [Ureter] explode all trees OR (nephrectomy* OR cystectomy* OR ureter OR ureteral OR ureters):ti,ab,kw

====================================================================

NOTE: FOR ALL SEARCH RESULTS, ANIMAL-ONLY STUDIES WERE DELETED MANUALLY IN ENDNOTE

NOTE: FOR ALL SEARCH RESULTS, ENDNOTE SEARCHES WERE DONE ON THE FOLLOWING TERMS INI THE RECORD TITLE OR KEYWORD:

- PEDIATRIC(S)
- PAEDIATRIC(S)
- CHILD(REN)
- INFANT(S)

RESULTS WERE REVIEWED AND ARTICLES RELATING ONLY TO NON-ADULT POPULATIONS WERE DELETED

IN ADDITION, ARTICLES FROM JOURNALS WITH “PEDIATRIC(S)” OR “PAEDIATRIC(S)” IN THE JOURNAL NAME WERE DELETED