# REFERENCES

1 Pernar LIM, Robertson FC, Tavakkoli A, Sheu EG, Brooks DC, Smink DS. An appraisal of the learning curve in robotic general surgery. Surgical endoscopy. 2017;31(11):4583–4596.28411345
2 Childers CP, Maggard-Gibbons M. Estimation of the Acquisition and Operating Costs for Robotic Surgery. JAMA. 2018;320(8):835–836.30167686
3 Tsui C, Klein R, Garabrant M. Minimally invasive surgery: national trends in adoption and future directions for hospital strategy. Surgical endoscopy. 2013;27(7):2253–2257.23660720
4 Rutkow IM. Demographic and socioeconomic aspects of hernia repair in the United States in 2003. The Surgical clinics of North America. 2003;83(5):1045–1051, v–vi.14533902
5 Peters BS, Armijo PR, Krause C, Choudhury SA, Oleynikov D. Review of emerging surgical robotic technology. Surgical endoscopy. 2018;32(4):1636–1655.29442240
6 Alemzadeh H, Raman J, Leveson N, Kalbarczyk Z, Iyer RK. Adverse Events in Robotic Surgery: A Retrospective Study of 14 Years of FDA Data. PLoS One. 2016;11(4):e0151470.27097160
7 Tsai AY, Selzer DJ. Single-port laparoscopic surgery. Advances in surgery. 2010;44:1–27.20919511
8 Cianci S, Rosati A, Rumolo V, . Robotic Single-Port Platform in General, Urologic, and Gynecologic Surgeries: A Systematic Review of the Literature and Meta-analysis. World journal of surgery. 2019;43(10):2401–2419.31187247
9 Higgins JP AD, Gøtzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. BMJ. 2011:343:d5928.22008217
10 Sterne JA HM, Reeves BC, . . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016:355:i4919.27733354
11 GRADE working group. 2014; http://www.gradeworkinggroup.org/.
12 Bittner Iv JG, Cesnik LW, Kirwan T, Wolf L, Guo D. Patient perceptions of acute pain and activity disruption following inguinal hernia repair: a propensity-matched comparison of robotic-assisted, laparoscopic, and open approaches. Journal of robotic surgery. 2018;12(4):625–632.29453731
13 Grochola LF, Soll C, Zehnder A, Wyss R, Herzog P, Breitenstein S. Robot-assisted versus laparoscopic single-incision cholecystectomy: results of a randomized controlled trial. Surgical endoscopy. 2019;33(5):1482–1490.30218263
14 Heemskerk J, Zandbergen HR, Keet SW, . Relax, it’s just laparoscopy! A prospective randomized trial on heart rate variability of the surgeon in robot-assisted versus conventional laparoscopic cholecystectomy. Digestive surgery. 2014;31(3):225–232.25277215
15 Kudsi OY, Castellanos A, Kaza S, . Cosmesis, patient satisfaction, and quality of life after da Vinci Single-Site cholecystectomy and multiport laparoscopic cholecystectomy: short-term results from a prospective, multicenter, randomized, controlled trial. Surgical endoscopy. 2017;31(8):3242–3250.27864724
16 Pietrabissa A, Pugliese L, Vinci A, . Short-term outcomes of single-site robotic cholecystectomy versus four-port laparoscopic cholecystectomy: a prospective, randomized, double-blind trial. Surgical endoscopy. 2016;30(7):3089–3097.26497946
17 Albrecht R, Haase D, Zippel R, Koch H, Settmacher U. [Robot-assisted surgery - Progress or expensive toy? : Matched-pair comparative analysis of robot-assisted cholecystectomy vs laparoscopic cholecystectomy]. Der Chirurg; Zeitschrift fur alle Gebiete der operativen Medizen. 2017;88(12):1040–1045.28660327
18 Main WPL, Mitko JM, Hussain LR, Meister KM, Kerlakian GM. Robotic versus Laparoscopic Cholecystectomy in the Obese Patient. The American surgeon. 2017;83(11):e447–e449.30454233
19 Angelos P. Can robotic approaches be justified for the benefit of surgeons? Surgery (United States). 2017;161(3):639–640.
20 Mitko J, Main W, Hussain L, Meister K, Kerlakian G, Tymitz K. Laparoscopic versus robotic cholecystectomy in the obese population: Is there a preferred approach? Surgery for Obesity and Related Diseases. 2016;12(7):S114–S115.
21 Eid JJ, Jyot A, Macedo FI, Sabir M, Mittal VK. Robotic Cholecystectomy Is a Safe Educational Alternative to Laparoscopic Cholecystectomy During General Surgical Training: A Pilot Study. Journal of surgical education. 2020.
22 Aggarwal R, Winter Beatty J, Kinross J, von Roon A, Darzi A, Purkayastha S. Initial Experience With a New Robotic Surgical System for Cholecystectomy. Surgical innovation. 2020;27(2):136–142.31771424
23 Balachandran B, Hufford TA, Mustafa T, Kochar K, Sulo S, Khorsand J. A Comparative Study of Outcomes Between Single-Site Robotic and Multi-port Laparoscopic Cholecystectomy: An Experience from a Tertiary Care Center. World journal of surgery. 2017;41(5):1246–1253.28058471
24 Chung PJ, Huang R, Policastro L, . Single-Site Robotic Cholecystectomy at an Inner-City Academic Center. JSLS : Journal of the Society of Laparoendoscopic Surgeons. 2015;19(3).
25 Hagen ME, Balaphas A, Podetta M, . Robotic single-site versus multiport laparoscopic cholecystectomy: a case-matched analysis of short- and long-term costs. Surgical endoscopy. 2018;32(3):1550–1555.29052069
26 Lee EK, Park E, Oh WO, Shin NM. Comparison of the outcomes of robotic cholecystectomy and laparoscopic cholecystectomy. Annals of surgical treatment and research. 2017;93(1):27–34.28706888
27 Lee SR, Kim HO, Shin JH. Clinical outcomes of single-incision robotic cholecystectomy versus conventional 3-port laparoscopic cholecystectomy. Canadian journal of surgery Journal canadien de chirurgie. 2019;62(1):52–56.30693746
28 Li YP, Wang SN, Lee KT. Robotic versus conventional laparoscopic cholecystectomy: A comparative study of medical resource utilization and clinical outcomes. The Kaohsiung journal of medical sciences. 2017;33(4):201–206.28359408
29 Wren SM, Curet MJ. Single-port robotic cholecystectomy: results from a first human use clinical study of the new da Vinci single-site surgical platform. Archives of surgery (Chicago, Ill : 1960). 2011;146(10):1122–1127.
30 Hagen ME, Balaphas A, Jung MK, Buchs NC, Buehler L, Morel P. Robotic single site versus multiport cholecystectomy: A case-matched analysis of short-and long-term costs. Surgical Endoscopy and Other Interventional Techniques. 2017;31:S53.
31 Teoh AY, Ng EK, Chan SM, Yip HC, Wong VW, Chiu PW. Endowrist equipped robotic laparoendoscopic single site access cholecystectomy versus 4 port laparoscopic cholecystectomy. A prospective comparative study. Surgical Endoscopy and Other Interventional Techniques. 2017;31:S328.
32 Abel SA, Al-Lami HS, Zeineddin S, Chandra A, Bingener-Casey J, Lyden ML. Robotic-Assisted Single Site Cholecystectomy and the Obese Patient: Single Center Outcomes Data. Journal of the American College of Surgeons. 2019;229(4):S112–S113.
33 Buzad FA, Corne LM, Brown TC, . Single-site robotic cholecystectomy: efficiency and cost analysis. The international journal of medical robotics + computer assisted surgery : MRCAS. 2013;9(3):365–370.23640914
34 Gonzalez AM, Rabaza JR, Donkor C, Romero RJ, Kosanovic R, Verdeja JC. Single-incision cholecystectomy: a comparative study of standard laparoscopic, robotic, and SPIDER platforms. Surgical endoscopy. 2013;27(12):4524–4531.23943118
35 Grochola LF, Soll C, Zehnder A, Wyss R, Herzog P, Breitenstein S. Robot-assisted single-site compared with laparoscopic single-incision cholecystectomy for benign gallbladder disease: results of a single-blinded randomized controlled trial. HPB. 2018;20:S726.
36 Gustafson M, Lescouflair T, Kimball R, Daoud I. A comparison of robotic single-incision and traditional single-incision laparoscopic cholecystectomy. Surgical endoscopy. 2016;30(6):2276–2280.26675933
37 Spinoglio G, Lenti LM, Maglione V, . Single-site robotic cholecystectomy (SSRC) versus single-incision laparoscopic cholecystectomy (SILC): comparison of learning curves. First European experience. Surgical endoscopy. 2012;26(6):1648–1655.22179472
38 Su WL, Huang JW, Wang SN, Lee KT. Comparison study of clinical outcomes between single-site robotic cholecystectomy and single incision laparoscopic cholecystectomy. Asian journal of surgery. 2017;40(6):424–428.27188234
39 Autin RL, Singh TP, Binetti B. Incidence of port site hernia following single site laparoscopic and robotic cholecystectomy. Surgical Endoscopy and Other Interventional Techniques. 2015;29:S469.
40 Jang EJ, Roh YH, Kang CM, Kim DK, Park KJ. Single-Port Laparoscopic and Robotic Cholecystectomy in Obesity (>25 kg/m2). JSLS : Journal of the Society of Laparoendoscopic Surgeons. 2019;23(2).
41 Lee JH, Song KB, Shin SH, Kim SC, Lee YJ, Park KM. Robotic single-site cholecystectomy of 520 cases: Surgical outcomes and comparing with laparoscopic single-site procedure. Surgical Endoscopy and Other Interventional Techniques. 2018;32(1):S351.
42 Lescouflair T, Gustafson M, Daoud I. A comparison of robotic single incision and traditional single incision laparoscopic cholecystectomy. Surgical Endoscopy and Other Interventional Techniques. 2014;28:286.
43 Moore MD, Abelson J, Tholey R, Panjwani S, Zarnegar R, Afaneh C. Robotic singleincision cholecystectomy, although a feasible and safe option, dramatically increases operative time when compared to single-incision laparoscopic cholecystectomy. Surgical Endoscopy and Other Interventional Techniques. 2016;30:S494.
44 Aragon RJ, Lin C, Vidovszky TJ, Carr AD, Ali MR. Innovative approaches to laparoscopic cholecystectomy: A comparison of outcomes for single incision laparoscopic cholecystectomy, multi-port robotic cholecystectomy, and single site robotic cholecystectomy. Surgical Endoscopy and Other Interventional Techniques. 2014;28:437.
45 Altieri MS, Yang J, Telem DA, . Robotic approaches may offer benefit in colorectal procedures, more controversial in other areas: a review of 168,248 cases. Surgical endoscopy. 2016;30(3):925–933.26139489
46 Farnsworth J, Surrusco M, Luo-Owen X, Yung E, Srikureja D, Mukherjee K. Is there a role for the robot in acute care surgery? Journal of investigative medicine. 2018;66(1):180–181.
47 Higgins RM, Frelich MJ, Bosler ME, Gould JC. Cost analysis of robotic versus laparoscopic general surgery procedures. Surgical Endoscopy and Other Interventional Techniques. 2016;30:S243.
48 Kitisin K, Packiam V, Celinski S, . Is the ever-expanding scope of robotics safe for hepatobiliary surgery too? HPB. 2011;13:33.21159101
49 Khorgami Z, Li WT, Jackson TN, Howard CA, Sclabas GM. The cost of robotics: an analysis of the added costs of robotic-assisted versus laparoscopic surgery using the National Inpatient Sample. Surgical endoscopy. 2019;33(7):2217–2221.30327915
50 Rosemurgy A, Ryan C, Klein R, Sukharamwala P, Wood T, Ross S. Does the cost of robotic cholecystectomy translate to a financial burden? Surgical endoscopy. 2015;29(8):2115–2120.25492447
51 Strosberg DS, Nguyen MC, Muscarella P, 2nd, Narula VK. A retrospective comparison of robotic cholecystectomy versus laparoscopic cholecystectomy: operative outcomes and cost analysis. Surgical endoscopy. 2017;31(3):1436–1441.27495346
52 Farukhi MA, Davis B. Robotic vs laparoscopic cholecystectomy: Which technique is optimal in morbidly obese patients? Surgical Endoscopy and Other Interventional Techniques. 2017;31:S327.
53 Ross S, Klein R, Ryan C, Toomey P, Sukharamwala P, Rosemurgy A. Does the cost of robotic cholecystectomy translate to a financial burden? Surgical Endoscopy and Other Interventional Techniques. 2014;28:247.
54 Strosberg DS, Nguyen MC, Muscarella IP, Narula VK. A retrospective comparison of robotic cholecystectomy versus laparoscopic cholecystectomy: Operative outcomes and cost analysis. Surgical Endoscopy and Other Interventional Techniques. 2016;30:S491.
55 Hawasli A, Sahly M, Meguid A, Edhayan E, Guiao C, Szpunar S. The impact of robotic cholecystectomy on private practice in a community teaching hospital. American journal of surgery. 2016;211(3):610–614.26806014
56 Pokala B, Flores L, Armijo PR, Kothari V, Oleynikov D. Robot-assisted cholecystectomy is a safe but costly approach: A national database review. American journal of surgery. 2019;218(6):1213–1218.31500796
57 Kane WJ, Charles EJ, Mehaffey JH, . Robotic compared with laparoscopic cholecystectomy: A propensity matched analysis. Surgery. 2020;167(2):432–435.31492434
58 Kaminski JP, Bueltmann KW, Rudnicki M. Robotic versus laparoscopic cholecystectomy inpatient analysis: does the end justify the means? Journal of gastrointestinal surgery : official journal of the Society for Surgery of the Alimentary Tract. 2014;18(12):2116–2122.25319034
59 Morris S, Patel N, Gurusamy K, Davidson B. Cost of robot versus human assistant in laparoscopic cholecystectomy. HPB. 2014;16:115.
60 Bedeir K, Mann A, Youssef Y. Robotic single-site versus laparoscopic cholecystectomy: Which is cheaper? A cost report and analysis. Surgical endoscopy. 2016;30(1):267–272.25861905
61 Higgins RM, Frelich MJ, Bosler ME, Gould JC. Cost analysis of robotic versus laparoscopic general surgery procedures. Surgical endoscopy. 2017;31(1):185–192.27139704
62 Newman RM, Umer A, Bozzuto BJ, Dilungo JL, Ellner S. Surgical Value of Elective Minimally Invasive Gallbladder Removal: A Cost Analysis of Traditional 4-Port vs Single-Incision and Robotically Assisted Cholecystectomy. Journal of the American College of Surgeons. 2016;222(3):303–308.26922602
63 Prabhu AS, Carbonell A, Hope W, . Robotic Inguinal vs Transabdominal Laparoscopic Inguinal Hernia Repair: The RIVAL Randomized Clinical Trial. JAMA surgery. 2020.
64 Switzer N, Renshaw S, Holcomb C, . 6-month post-operative quality of life and pain comparisons between robotic and laparoscopic inguinal hernia repair. Surgical Endoscopy. 2019;33:S372.
65 Waite KE, Herman MA, Doyle PJ. Comparison of robotic versus laparoscopic transabdominal preperitoneal (TAPP) inguinal hernia repair. Journal of robotic surgery. 2016;10(3):239–244.27112781
66 Kolachalam R, Dickens E, D’Amico L, . Early outcomes of robotic-assisted inguinal hernia repair in obese patients: a multi-institutional, retrospective study. Surgical endoscopy. 2018;32(1):229–235.28646321
67 Kosturakis AK, LaRusso KE, Carroll ND, Nicholl MB. First 100 consecutive robotic inguinal hernia repairs at a Veterans Affairs hospital. Journal of robotic surgery. 2018;12(4):699–704.29721702
68 Charles EJ, Mehaffey JH, Tache-Leon CA, Hallowell PT, Sawyer RG, Yang Z. Inguinal hernia repair: is there a benefit to using the robot? Surgical Endoscopy. 2018;32(4):2131–2136.29067575
69 Gamagami R, Dickens E, Gonzalez A, . Open versus robotic-assisted transabdominal preperitoneal (R-TAPP) inguinal hernia repair: a multicenter matched analysis of clinical outcomes. Hernia. 2018;22(5):827–836.29700716
70 Huerta S, Timmerman C, Argo M, . Open, Laparoscopic, and Robotic Inguinal Hernia Repair: Outcomes and Predictors of Complications. Journal of Surgical Research. 2019;241:119–127.
71 AlMarzooqi R, Tish S, Huang LC, Prabhu A, Rosen M. Review of inguinal hernia repair techniques within the Americas Hernia Society Quality Collaborative. Hernia. 2019;23(3):429–438.31069581
72 Kakaishvili EK, Brauner EB, Kluger YK. Robotic inguinal hernia repair: Is it a new era in the surgical management of groin hernia? Surgical Endoscopy. 2018;32:S485.
73 Muysoms F, Van Cleven S, Kyle-Leinhase I, Ballecer C, Ramaswamy A. Robotic-assisted laparoscopic groin hernia repair: observational case-control study on the operative time during the learning curve. Surgical Endoscopy. 2018;32(12):4850–4859.29766308
74 Kudsi OY, McCarty JC, Paluvoi N, Mabardy AS. Transition from Laparoscopic Totally Extraperitoneal Inguinal Hernia Repair to Robotic Transabdominal Preperitoneal Inguinal Hernia Repair: A Retrospective Review of a Single Surgeon’s Experience. World journal of surgery. 2017;41(9):2251–2257.28337532
75 Abdelmoaty WF, Dunst CM, Neighorn C, Swanstrom LL, Hammill CW. Robotic-assisted versus laparoscopic unilateral inguinal hernia repair: a comprehensive cost analysis. Surgical endoscopy. 2019;33(10):3436–3443.30535936
76 Zayan NE, Meara MP, Schwartz JS, Narula VK. A direct comparison of robotic and laparoscopic hernia repair: patient-reported outcomes and cost analysis. Hernia. 2019.
77 Janjua H, Cousin-Peterson E, Barry TM, Kuo MC, Baker MS, Kuo PC. The paradox of the robotic approach to inguinal hernia repair in the inpatient setting. American Journal of Surgery. 2020;219(3):497–501.31558306
78 Khoraki J, Gomez PP, Mazzini GS, . Perioperative outcomes and cost of robotic-assisted versus laparoscopic inguinal hernia repair. Surgical Endoscopy. 2019.
79 Sheldon RR, Do WS, Weiss JB, Forte DM, Sohn VY. Sage wisdom or anecdotal dictum? Equivalent opioid use after open, laparoscopic, and robotic inguinal hernia repair. American journal of surgery. 2019;217(5):839–842.30827531
80 Knott LT, Shih IF, Song C, Paul Singh T. Comparison of robotic-assisted, laparoscopic and open surgery in primary inguinal hernia repair. Surgical Endoscopy and Other Interventional Techniques. 2018;32(1):S46.
81 Macias AE, Jacome F, Punshon J. Inguinodynia-tastic: A comparison between robotic and laparoscopic inguinal hernia repair. Journal of the American College of Surgeons. 2017;225(4):e88.
82 Pokala B, Armijo PR, Flores L, Hennings D, Oleynikov D. Minimally invasive inguinal hernia repair is superior to open: a national database review. Hernia. 2019;23(3):593–599.31073960
83 Lammers DT, Kuckelman JP, Bingham J. 51.03 Comparison of Robotic Versus Laparoscopic and Open Repair for Inguinal Hernias. Madigan Army Medical Center, Department Of General Surgery 2019.
84 Holcomb CN, Huang LC, Renshaw S, . Wound complications after inguinal hernia repair, has robotic surgery improved outcomes? Surgical Endoscopy. 2019;33:S362.
85 Abdalla R, Santo M, Gontijo C, Frade Said D, Cecconello I, Costa T. Randomized clinical trial: camparison between robotic assited and laparoscopic incisional hernia repair. Hernia. 2017;21(1):S115-.
86 Bittner JGt, Alrefai S, Vy M, Mabe M, Del Prado PAR, Clingempeel NL. Comparative analysis of open and robotic transversus abdominis release for ventral hernia repair. Surgical endoscopy. 2018;32(2):727–734.28730275
87 Martin-Del-Campo LA, Weltz AS, Belyansky I, Novitsky YW. Comparative analysis of perioperative outcomes of robotic versus open transversus abdominis release. Surgical endoscopy. 2018;32(2):840–845.28733746
88 Nguyen B, David B, Gosch K, Sorensen GB. Comparisons of abdominal wall reconstruction for ventral hernia repairs, open versus robotic. Surgical Endoscopy. 2019;33:S354.
89 Switzer N, Renshaw S, Holcomb C, . Evaluating abdominal wall function post ventral hernia repair: A comparison of open versus robotic-assisted retromuscular techniques. An americas hernia society quality collaborative study. Surgical Endoscopy. 2019;33:S362.
90 Carbonell AM, Warren JA, Prabhu AS, . Reducing Length of Stay Using a Robotic-assisted Approach for Retromuscular Ventral Hernia Repair: A Comparative Analysis From the Americas Hernia Society Quality Collaborative. Annals of surgery. 2018;267(2):210–217.28350568
91 A. Guzman-Pruneda F, Huang LC, Collins C, Renshaw S, Narula V, B KP. Abdominal core quality of life after ventral hernia repair: a comparison of open versus robotic-assisted retromuscular techniques. Surgical Endoscopy. 2020.
92 Roberts SH, Rodman CP, Meara MP. Short-Term Outcomes of Robotic vs Open Transversus Abdominus Release. Journal of the American College of Surgeons. 2019;229(4):e128.
93 Lu R, Addo A, Ewart Z, . Comparative review of outcomes: laparoscopic and robotic enhanced-view totally extraperitoneal (eTEP) access retrorectus repairs. Surgical Endoscopy. 2019.
94 Khorgami Z, Li WT, Jackson TN, Howard CA, Sclabas GM. The cost of robotics: an analysis of the added costs of robotic-assisted versus laparoscopic surgery using the National Inpatient Sample. Surgical Endoscopy. 2019;33(7):2217–2221.30327915
95 Gonzalez AM, Romero RJ, Seetharamaiah R, Gallas M, Lamoureux J, Rabaza JR. Laparoscopic ventral hernia repair with primary closure versus no primary closure of the defect: potential benefits of the robotic technology. The international journal of medical robotics + computer assisted surgery : MRCAS. 2015;11(2):120–125.25236697
96 Prabhu AS, Dickens EO, Copper CM, . Laparoscopic vs Robotic Intraperitoneal Mesh Repair for Incisional Hernia: An Americas Hernia Society Quality Collaborative Analysis. Journal of the American College of Surgeons. 2017;225(2):285–293.28450062
97 Walker PA, May AC, Mo J, . Multicenter review of robotic versus laparoscopic ventral hernia repair: is there a role for robotics? Surgical Endoscopy. 2018;32(4):1901–1905.29411133
98 Coakley KM, Sims SM, Prasad T, . A nationwide evaluation of robotic ventral hernia surgery. American journal of surgery. 2017;214(6):1158–1163.29017732
99 Altieri MS, Yang J, Xu J, Talamini M, Pryor A, Telem DA. Outcomes after Robotic Ventral Hernia Repair: A Study of 21,565 Patients in the State of New York. The American surgeon. 2018;84(6):902–908.29981622
100 Chen YJ, Huynh D, Nguyen S, Chin E, Divino C, Zhang L. Outcomes of robot-assisted versus laparoscopic repair of small-sized ventral hernias. Surgical endoscopy. 2017;31(3):1275–1279.27450207
101 Warren JA, Cobb WS, Ewing JA, Carbonell AM. Standard laparoscopic versus robotic retromuscular ventral hernia repair. Surgical endoscopy. 2017;31(1):324–332.27287903
102 Mudyanadzo TA, Hunter JD, Rider PF, Richards WO. An Evaluation of Robotic Ventral Hernia Repair. The American surgeon. 2020;86(1):e45–e46.32077437
103 Song C, Liu E, Shi L, Marcus D. Comparative effectiveness for ventral hernia repairs among an obese patient population. Surgical Endoscopy and Other Interventional Techniques. 2017;31:S136.
104 Armijo P, Pratap A, Wang Y, Shostrom V, Oleynikov D. Robotic ventral hernia repair is not superior to laparoscopic: a national database review. Surgical Endoscopy. 2018;32(4):1834–1839.29052065
105 Makra GM, Dechantsreiter G, Holzapfel K. ROFO Fortschr Geb Rontgenstr Nuklearmed. 2019;191(1):67–69.30308692
106 Hagen ME, Jung MK, Fakhro J, . Robotic versus laparoscopic stapling during robotic Roux-en-Y gastric bypass surgery: a case-matched analysis of costs and clinical outcomes. Surgical endoscopy. 2018;32(1):472–477.28726136
107 Tan WH, McAllister J, Feaman S, Blatnik JA. Cost comparison of laparoscopic versus robotic ventral hernia repairs. Surgical Endoscopy and Other Interventional Techniques. 2018;32(1):S18.
108 Lim JH, Lee WJ, Park DW, Yea HJ, Kim SH, Kang CM. Robotic cholecystectomy using Revo-i Model MSR-5000, the newly developed Korean robotic surgical system: a preclinical study. Surgical endoscopy. 2017;31(8):3391–3397.27873012
109 Tom CM, Maciel JD, Korn A, . A survey of robotic surgery training curricula in general surgery residency programs: How close are we to a standardized curriculum? American journal of surgery. 2019;217(2):256–260.30518480
110 George LC, O’Neill R, Merchant AM. Residency Training in Robotic General Surgery: A Survey of Program Directors. Minim Invasive Surg. 2018;2018:8464298.29854454
111 Carpenter BT, Sundaram CP. Training the next generation of surgeons in robotic surgery. Robot Surg. 2017;4:39–44.30697562
112 Wee IJY, Kuo LJ, Ngu JC. A systematic review of the true benefit of robotic surgery: Ergonomics. The international journal of medical robotics + computer assisted surgery : MRCAS. 2020:e2113.32304167
113 Lee GI, Lee MR, Green I, Allaf M, Marohn MR. Surgeons’ physical discomfort and symptoms during robotic surgery: a comprehensive ergonomic survey study. Surgical endoscopy. 2017;31(4):1697–1706.27515836
114 Dwyer A, Huckleby J, Kabbani M, Delano A, De Sutter M, Crawford D. Ergonomic assessment of robotic general surgeons: a pilot study. Journal of robotic surgery. 2020;14(3):387–392.31302826
115 Patel SV, Yu D, Elsolh B, Goldacre BM, Nash GM. Assessment of Conflicts of Interest in Robotic Surgical Studies: Validating Author’s Declarations With the Open Payments Database. Annals of surgery. 2018;268(1):86–92.28700443
116 Calatayud D, Kakarla VR, Coratti F, . Minimally invasive cholecystectomy-retrospective study comparing laparoscopic vs robotic approach. Surgical Endoscopy and Other Interventional Techniques. 2012;26:S413.