# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by Dr. Mark Wilson, National Director of Surgery, and Dr. William Gunnar, Executive Director, National Center for Patient Safety and former National Director of Surgery. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Roberta Shanman, Jon Bergman, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Mark Wilson, MD, PhD
  National Director of Surgery
  Department of Veterans Affairs
- William Gunnar, MD
  Executive Director, National Center for Patient Safety
  Former National Director of Surgery
  Department of Veterans Affairs

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Bryanna Emr, MD
  General Surgeon, Clinical Assistant Professor, University of Pittsburgh and VA Pittsburgh Healthcare System
- Timothy Frankel, MD
  Assistant Professor, General Surgery and Surgical Oncology, University of Michigan Hospitals-Michigan Medicine and Veterans Affairs Ann Arbor Healthcare System
- Tomas Heimann, MD
  Professor of Surgery, Colorectal Surgeon, Mount Sinai Hospital, New York, Chief of Surgery at James J. Peters VA Medical Center in New York, an affiliate of the Mount Sinai School of Medicine.
- Frederick Luchette, MD
  Chief of Surgical Service Line, Edward Hines Jr., VA Hospital; Professor of Surgery, Department of Surgery Stritch School of Medicine, Loyola University of Chicago

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.