# SUMMARY AND DISCUSSION

## SUMMARY OF EVIDENCE BY KEY QUESTION

### Key Question 1A What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for cholecystectomy?

In general, OR time was longer in patients treated with robot-assisted cholecystectomy compared to laparoscopic cholecystectomy. While not always statistically significant, data are consistent across RCTs and observational studies. There was no evidence of differences in total intra-operative complications or conversions, and most studies had point estimates close to the null value. Only 5 studies reported common bile duct injuries, and there was no evidence of a difference between robot-assisted cholecystectomy and laparoscopic cholecystectomy. Most studies did not demonstrate a significant difference in LOS, postoperative complications, or surgical site infections. Pain was variable among the studies and did not demonstrate a pattern. The rate of incisional hernia may be higher in the robot-assisted cholecystectomy cohort when performed using a single-port compared to a multi-port laparoscopic surgery. This finding is not unexpected and may not be an appropriate comparison, as the single-port robot-assisted cholecystectomy requires a larger incision than the smaller incisions needed for the multi-port laparoscopic cholecystectomy. Studies comparing single-port robot-assisted assisted cholecystectomy and single-port laparoscopic cholecystectomy were not different in hernia outcomes. This is an important consideration, since the single-port approach with robot-assisted cholecystectomy or laparoscopic cholecystectomy involves a larger incision and confers a higher risk for developing an incisional hernia. Thus, the interpretation of this finding may be related to single-port versus multi-port, not robot versus laparoscopic.

### Key Question 2A What is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for cholecystectomy?

While there are a number of studies comparing the cost-effectiveness of robot-assisted versus laparoscopic surgery for cholecystectomy, all had significant limitations, primarily surrounding the cost methodology. None were formal cost-effectiveness analysis studies. Nevertheless, there was an almost unanimous finding, including in the randomized data, that the robot-assisted approach is more expensive than the laparoscopic approach. We therefore have moderate certainty that robot-assisted surgery is more expensive than laparoscopic cholecystectomy.

### Key Question 1B What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for inguinal hernia repair?

Operative room time was longer in patients treated with robot-assisted inguinal hernia repair compared to laparoscopic and open repair, particularly for unilateral repairs. In terms of LOS, there may be a signal of a small benefit favoring the robot-assisted approach compared to open surgery for inpatient stays. There does not appear to be a signal of benefit with regard to SSI for the robot-assisted approach compared to laparoscopic or open surgery. There may be a small signal of benefit for lower readmissions with the robot-assisted approach for unilateral hernias. Most studies demonstrated no difference among approaches when assessing complications and postoperative pain. There was no difference in hernia recurrence among all approaches.

### Key Question 2B What is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for inguinal hernia repair?

Only 5 studies compared costs of robot-assisted compared to laparoscopic or open surgery for inguinal hernia repair. All had significant limitations, primarily surrounding the cost methodology. Robot-assisted surgery was more expensive in these studies as compared to laparoscopic or open inguinal hernia repair. Based on somewhat limited directness and consistency in the evidence, we have low certainty that robot-assisted surgery is more expensive than laparoscopic or open surgery for inguinal hernia repair. Importantly, since there were no formal cost-effectiveness analyses, no conclusion can be made in this regard as well.

### Key Question 1C What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for ventral hernia repair?

Operating room time was longer in patients who underwent robot-assisted ventral hernia repair compared to both the open approach and laparoscopic approach. This was an almost universal finding among all the studies evaluating this outcome. Conversion to open surgery from a robot-assisted approach may be less than from a laparoscopic approach. This finding was demonstrated in 1 matched^103^ and 1 unmatched study^101^ with a third study^95^ showing no difference. LOS also may be favored by performing a robot-assisted surgery for ventral hernia. This was a statistically significant difference between robot-assisted and open ventral hernia repair; however, this effect was not shown when compared to the laparoscopic approach. There was no evidence of differences in readmissions, SSI, postoperative complications, and mortality. The outcome of recurrence was evaluated in 1 matched study^96^ and 5 unmatched studies^76,89,93,95,97^ showing no significant difference except in the matched study. Only 2 studies evaluated postoperative pain, which showed no difference between the groups of patients.^96,101^

### Key Question 2C What is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for ventral hernia repair?

There are a handful of cases comparing the costs of robot-assisted versus laparoscopic or open surgery for ventral hernia repair. All had significant limitations, primarily surrounding the cost methodology. However, 4 of the 6 studies reported that the robot-assisted approach was more expensive than either the laparoscopic or open approach (with large effect size) and the other 2 studies reported no difference in cost as compared to laparoscopic repair. As seen for cholecystectomy and inguinal hernia, no cost-effectiveness studies were identified.

## LIMITATIONS

### Publication Bias

We were not able to test for publication bias and can make no conclusions about its possible existence. However, we believe it is extremely unlikely that there exists a high-quality randomized trial of robot-assisted surgery versus other surgical approaches that we did not identify, and has similarly escaped detection by all other experts in this field. There are probably a plentitude of observational experiences about robotic therapies, from individual institutions, that have never been published, and the published literature likely represents only a small fraction of what could be known using observational studies.

### Study Quality

The randomized trials for were judged to be at low risk of bias for short-term outcomes, like intraoperative and postoperative outcomes. They were judged to be at moderate risk of bias for longer-term outcomes. Likewise, the observational studies were judged to be at moderate risk of bias (due to their non-random assignment of treatments) for short-term outcomes and high risk of bias for longer-term outcomes.

### Heterogeneity

As mentioned, the studies were very heterogeneous across patient and technique factors as well as how the outcomes were measured. Since we only found 4 RCTS for cholecystectomy, 1 for inguinal hernia repair, and 1 small RCT for ventral hernia repair, the vast majority of our data was observational. There are potential strong selection biases by the surgeons for when they would choose to perform a robot-assisted case over the standard approaches – which often leads to differences in the comparative groups, which we saw in the studies included in our review. The technique used for the robot-assisted approach is also different – how the mesh is secured, fascial closure, bilateral repair, or number of ports.

Some outcomes had heterogeneous measurements across studies. These included: OR time, LOS, and pain. OR time was most commonly reported as skin cut time to closure, but others reported the room time, console time, or didn’t define their measurement. Length of stay was also challenging to compare across studies as these operations could be performed as outpatient or inpatient and there was often a mix of time scale between or within studies. Pain as an outcome was reported using a variety of measures: different scales, variable time intervals, receipt of pain medications, time needing pain medication, and occurrence of chronic nerve pain. This greatly limited the ability to compare results across studies.

### Applicability of Findings to the VA Population

Only 2 studies were specific to VA populations – 1 for cholecystectomy^29^ and 1 for inguinal hernia repair^67^ – therefore strong conclusions from this data cannot be made. Unfortunately, we are not aware of any robotic cost data within the VA, but utilization data is available and this may serve as a first step towards future research in this area.

However, the applicability of these results to VA populations may depend on both the similarity of the patients studied to VA patients and the experience of the surgical teams using the robot to VA surgical team experience. Yet the benefits for robot-assisted approach may still be realized despite patient-level differences (VA patient population has greater burden of comorbidities than the general population), which will need to be confirmed in future studies. Urology as a surgical field has widely adopted robot-assisted surgery, so this experience will likely translate well into the expansion of robot-assisted approach to general surgery in the VA setting.

### Research Gaps/Future Research

Numerous research gaps are apparent. There is a need for randomized data or propensity matching that addresses patient- and technique-related factors. The variability in the use of the robot-assisted approach based on these factors currently limits the ability to compare across study arms, as variations at baseline or differences in how the operation was performed are large and may likely be responsible for realized clinical differences or lack thereof. Importantly, there are advantages of the robot that are clear and notable – enhanced, three-dimensional visualization, augmented dexterity and range of motion, reduction of tremor, to name a few. The heterogeneous nature of the studies limited the ability to show how these features translate into better clinical outcomes. Studies that control for key patient factors, case complexity, technical aspects of procedures, and surgeon experience may provide insight into this overarching question. Additionally, adequate long-term follow-up for certain outcomes is greatly needed. Several areas warrant specific discussion.

#### Surgeon Learning Curve

The surgeon learning curve is a well-characterized surgical concept that has similarly been applied to robot-assisted surgery. As with any new platform the need for training, practice, and experience is needed. Even open surgical procedures, such as pancreatectomy, suffer from inexperienced surgeons that require tutelage before displaying mastery of the technique. The advent of laparoscopy more than 30 years ago brought this concept more into the forefront and showed the impact of surgeon learning curves on clinical patient outcomes. Likewise, surgeon learning curve for robot-assisted cases is a multifaceted issue. Previous reviews found that the surgeon experience (ie, ability as a function of cases completed) is fluid, as it has multiple phases and surgeons tend to add increasingly complex patient cases as they gain experience.^1^ In our review, we found that 90% of the studies for robot-assisted cholecystectomy acknowledged the possibility of a learning curve; however, only 5/46 provided data/assessment (and findings on OR time and incisional hernia occurrence were mixed).^22,23,29,34,37^ A learning curve impact may likely vary by procedure as well. Research assessing surgeon experience needs to include a variety of clinical outcomes, not just efficiency such as OR time. With emerging technologies, research should routinely comment on and address the potential impact the level of experience of the surgeon or surgeons played.

#### Resident Training

Robotics as an evolving technology is also changing how surgical residents are educated. Furthermore, faculty surgeons need to gain their own experience while balancing training residents. 1 recent survey of program directors by Tom et al found that a 92% of programs have residents participating in robot-assisted surgery, while 68% offer formal curriculum; 44% track residents’ robot-assisted experience, and about half (55%) recognize curriculum training completion.^109^ Another study also found wide variations “in requisite components, formal credentialing, and case tracking and role of simulation training”.^110^ There is also no standardized approach on how to incorporate this training based on level of trainee. Overall, there is a need to adopt a standardized training curriculum and document resident competency.^111^

#### Long-term Follow-up

Our work identified a lack of high-quality evidence with adequate long-term follow-up and sufficient statistical power to properly assess clinical outcomes between the operative approaches for inguinal hernia repair and ventral hernia repairs. For hernia repairs, outcomes of interest need to include recurrent hernias beyond 1 year, long-term pain, and functional status. Only 1 small RCT was found for ventral hernia repair, none for inguinal, and it only reported on 1 main outcome of interest. The data we found was too limited to provide conclusions in this regard.

#### Cholecystectomy Research Gaps

Our review focused on use of robot-assisted surgery for benign, elective gallbladder disease. However, there is a need for future studies on cholecystectomy for non-benign pathology and emergent cases. As the robot-assisted technique is becoming more common, certain institutions are beginning to use it for cancer cases and non-elective surgeries, which are notably more complex. Given the differences in patient populations that experience these indications and the higher rates of complications for non-elective surgeries, the results from our study may not be generalizable to these populations. In fact, the robot-assisted approach may prove to be particularly advantageous for these more complex cases. The study of differences in cancer outcomes, and morbidity, for robot-assisted versus laparoscopic and open surgery is essential. As such, future research may consider expanding this review to examine different indications for cholecystectomy.

#### Inguinal Hernia and Ventral Hernia Repair Research Gaps

Specific to hernia repairs, the robot-assisted approach may offer several technical advantages. For inguinal hernias, the potential for avoiding tacks or even the need for suturing mesh (sutureless mesh) may lead to less postoperative acute and chronic pain. For ventral hernia, the robot-assisted approach with improved suturing technique can also forego placement of tacks as well as possibly decrease recurrent hernia formation. Unfortunately, these technical details were not uniformly available across the studies in our review and outcomes were typically not reported by these factors. As such, it was not possible to determine their specific roles. Additionally, baseline pain was often not reported, perioperative quality of life and pain data were sparse, and long-term data on chronic pain and recurrence were rare. Standardized reporting in future work is needed in order to sufficiently assess pain outcomes. Guidance should be provided on reporting technical aspects of the repair and requirements for clinical outcome assessment – for instance, specific time intervals, tools for assessing pain, and amount of pain medications taken.

#### Ergonomics for the Surgeon

An important issue that deserves study is the impact of the robot-assisted approach on the physical stress on the surgeon performing the operation. There is a high rate of musculoskeletal disorders attributed to poor ergonomics of laparoscopic surgery as well as the open approach. There are those that claim robot-assisted surgery ergonomics are superior, leading to decreased physical stress and workload. However, there is also growing evidence that a prolonged time sitting at the robot-assisted console adds new physical challenges as well.^112^ Two recent studies reported physical discomfort and symptoms^113^ or poor posture^114^ in over half of surgeons. Although data are sparse, it would be a valuable area for future research. While challenging to study, the outcomes would need to be comparative, long-term (5 year plus) and would require assessing detailed quality of life, assessment of chronic physical injuries, and longevity of operating over a career.

#### Future Innovation in Surgical Robotics

An overwhelming number of the studies in our review used the da Vinci system from Intuitive (only 1 study used the Senhance robot).^22^ The robotic field is changing soon, as a number of new robotic platforms are becoming available; there are 8 with FDA approval, and more pending approval.^5^ These will bring with them potentially new advantages (eg, improved computer optics, machine learning, and automation) and possibly new challenges (eg, different technology with new learning curves, unknown impact on patient outcomes). Future research will be critical to assess the differences between these technologies. With these new market forces, there is anticipation for reduced cost as well.

#### Conflict of Interest

It is notable that reporting bias in robot-assisted surgery research has been identified. A recent study found that author payments from Intuitive were not declared in more than half (52%) of robot-assisted surgery research,^115^ and they reported more positive findings as compared to those that did declare their conflict of interest (COI) payments. There is a need to ensure full disclosure of COI with more accountability and journals may want to adopt standardized processes to achieve better transparency.

#### Costs

Lastly, the lack of well-designed comparative studies also limits evaluations of cost. There is a need for standardized approaches to assess cost, which would apply to all 3 of these robot-assisted operations (ie, analytics approach, consistent definitions of cost, how upfront capital was accounted for, how to adjust for training staff, etc). Along these lines, formal cost-effectiveness studies that weigh the benefits and risks along with cost are needed.

### Conclusions

Across 3 common general surgery procedures there is evidence that OR time is longer for the robot-assisted approach, and some signals that select intraoperative and postoperative complications are more favorable with the robot-assisted approach based on the operation. Overall, the studies were heterogeneous in terms of patient characteristics and how the operations were performed and definitive conclusions cannot be made. Cost is probably higher across these procedures, but the balance between the added expense and potential gains in effectiveness are unknown, until we adopt better, standardized methods of assessment.