# RESULTS

For cholecystectomy, we identified 887 potentially relevant citations, of which 169 were included at the abstract screening. From these, a total of 90 abstracts were excluded. Excluded abstracts were categorized as wrong comparison (n=54), systematic review (n=14), review/editorial (n=14), no outcome of interest (n=1), and other (n=7). This left 79 publications for full-text review, of which 32 were excluded for the following reasons: wrong comparison (n=4), no clinical data (n=3), no outcome of interest (n=4), review/editorial (n=8), other (n=2), and duplicate (n=11). A full list of excluded studies from the full-text review is included in Appendix H. A total of 47 publications were identified at full-text review as meeting initial inclusion criteria: RCT with cost and clinical data (n=1), RCTs with clinical data only (n=3), observational studies with cost data only (n=3), observational studies with clinical outcomes only (n=25), and observational studies with both clinical and cost data (n=15). Descriptions of included publications are available in the Evidence Table (Appendix G).

For inguinal hernia repair, we identified 3,319 potentially relevant citations and 9 publications recommended by experts. From these, 185 were included for abstract screening. A total of 143 abstracts were excluded, categorized as wrong comparison (n=129), no outcome of interest (n=1), other (n=6), systematic review (n=3), review (n=1), and duplicate (n=3). This left 42 publications for full-text review, of which 19 were excluded for the following reasons: wrong comparison (n=2), no outcome of interest (n=6), no clinical data (n=3), procedure (n=1), systematic review (n=1), review/editorial (n=2), duplicate (n=3), and unavailable (n=1). A full list of excluded studies from the full-text review is included in Appendix H. A total of 23 publications were identified at full-text review as meeting initial inclusion criteria: RCT with clinical and cost data (n=1), observational studies with clinical outcomes only (n=18), and observational studies with both clinical and cost data (n=4). Eleven studies had known hernia laterality that were similar distribution between study arms (<25% difference in laterality). While 6 studies with known laterality had >25% difference between comparison groups, for the other 6 studies, laterality was unknown or not reported (between the comparative arms). Descriptions of included publications are available in the Evidence Table (Appendix G).

For ventral hernia repair, we identified 3,458 potentially relevant citations and 5 publications recommended by experts. From these, 369 were included for abstract screening. A total of 321 abstracts were excluded, categorized as wrong comparison (n=306), review/editorial (n=8), no outcome of interest (n=8), systematic review (n=1), and duplicate (n=3). This left 48 publications for full-text review, of which 26 were excluded for the following reasons: case series with sample less than 10 (n=2), comparison (n=6), no outcome of interest (n=7), sample size less than 10 in each arm (n=2), review/editorial (n=1), systematic review (n=1), duplicate (n=6), and unavailable (n=1). A full list of excluded studies from the full-text review is included in Appendix H. A total of 22 publications were identified at full-text review as meeting initial inclusion criteria: RCT with clinical data only (n=1), observational study with cost data only (n=1), observational studies with clinical data only (n=15), and observational studies with both clinical and cost data (n=5). 7 of the observational studies reported matched data and 14 had unmatched data. Descriptions of included publications are available in the Evidence Table (Appendix G).

## THE RISK OF BIAS OF STUDIES

For cholecystectomy, there were 4 RCTs and 40 observational studies. The RCTs in general were assessed to have an overall low risk of bias. Overall, the majority of the observational studies had high to moderate risk of bias, except for those with propensity matching (n=4).

For inguinal hernia repair, 1 RCT and 22 observational studies met inclusion criteria, including 6 abstracts. The RCT was assessed to have an overall moderate risk of bias due to the single-blinded design, unclear allocation concealment and blinding of outcome assessment, and potential for author bias due to the significant funding to multiple authors by the robot manufacturer. Overall, the majority of the observational studies had a high risk of confounding bias, as only 5 studies were propensity matched. Large differences (>25%) in or lack of reporting of the proportion of unilateral to bilateral inguinal hernia repairs also introduced confounding bias in 10 observational studies. Selection bias for the majority of studies was low; however, 8 studies were judged to have greater risk of bias due to study-specific patient exclusion criteria. Several papers also had author disclosures due to involvement with Intuitive Surgical Inc. Finally, we identified 1 study that conducted a random sample from a web-based research panel and was subject to numerous methodological limitations due to low response rate and high recall bias.^12^

For ventral hernia repair, 1 RCT and 20 observational studies met inclusion criteria. The RCT was a conference abstract of a small sample of patients and was judged to have an overall high risk of bias due to lack of allocation concealment, blinding of patients and personnel, blinding of outcome assessment, selective reporting, and use of self-reported outcomes, such as quality of life. The majority of the observational studies had a high risk of confounding bias, as only 8 studies were propensity matched, and of the matched studies, there was variation on which variables were being matched (eg, patient characteristics vs hernia size). Selection bias was overall low.

For all procedures, bias in the measurement classification of interventions, bias due to deviation from intended interventions, and bias in selection of the reported result were generally low. Bias due to missing data was overall low, as most studies only reported short-term (≤ 30 day) outcomes, which were presumed to have minimal loss to follow-up. Studies with long-term outcomes had a higher risk of bias due to missing data if follow-up rates were low or not reported. For bias in measurement of outcomes, self-reported outcomes relating to pain and quality of life had a moderate risk of bias due to the subjectivity of these measurements, while objective assessments of pain, such as narcotic use, had a low risk of bias. Other outcomes, such as length of stay, complications, and OR time, had a low risk of bias.

Figure 1A Literature Flow Chart

CHOLESCYSTECTOMY

Figure 1B Literature Flow Chart

INGUINAL HERNIA REPAIR

Figure 1C Literature Flow Chart

VENTRAL HERNIA REPAIR

## KEY QUESTION 1A CHOLECYSTECTOMY: What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic surgery for cholecystectomy?

We identified 44 publications that met the inclusion criteria; 4 studies were randomized trials,^13–16^ and the remaining studies were observational. 7 studies compared multi-port robot-assisted cholecystectomy with multi-port laparoscopic cholecystectomy,^14,17–22^ including 1 RCT^14^; 12 compared single-port robot-assisted cholecystectomy with multi-port laparoscopic cholecystectomy,^15,16,23–32^ including 2 RCTs^15,16^; and 11 compared single-port robot-assisted cholecystectomy with single-port laparoscopic cholecystectomy,^33–43^ including 1 RCT.^13^ 1 study compared 3 arms: single-port robot-assisted cholecystectomy, multi-port robot-assisted cholecystectomy, and single-port laparoscopic cholecystectomy.^44^ Thirteen studies either grouped all (single and multi-port) robot-assisted and laparoscopic cholecystectomies in separate groups or did not specify if the robot and laparoscopic arms were single-port, multi-port, or both.^45–57^ The studies varied in size from 20 to 735,537 patients.

Figure 2 presents graphically the results for 4 intraoperative outcomes: operating room (OR) time, complications, conversion to open cholecystectomy (or conversion from robot-assisted to laparoscopic cholecystectomy), and common bile duct injury. In the 4 RCTs, OR time was consistently longer for robot-assisted cholecystectomy procedures, although these differences were only statistically significant in 2 studies (one compared single-port robot-assisted cholecystectomy to single-port laparoscopic cholecystectomy^15^ and the other multi-port robot-assisted cholecystectomy to multi-port laparoscopic cholecystectomy).^14^ From the observational studies, robot-assisted cholecystectomy took longer to perform in the great majority of studies with most of these differences being statistically significant. Of the studies that demonstrated a shorter OR time in the robot cohort, only 2 were statistically significant, and they compared single-port robot-assisted cholecystectomy and single-port laparoscopic cholecystectomy.^37,41^ For the outcomes of intraoperative complications, bile duct injury as its own outcome, or conversion rates, differences between robot-assisted cholecystectomy and comparison procedures were minimal to none, both in the RCTs and in the observational studies.

Figure 2 Cholecystectomy Intraoperative Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted cholecystectomy and laparoscopic approach. RCTs are listed in the left-hand side, while observational studies are listed on the right-hand side.

Figure 3 presents graphically the results of 6 short-term outcomes: LOS, all postoperative complications, surgical site infections, pain immediately following surgery, pain 1-30 days, and readmission rate. 3 out of 4 RCTs^13,15,16^ reported on LOS, and this was significantly shorter in 1 study comparing the single-port robot-assisted cholecystectomy patients with single-port laparoscopic cholecystectomy patients.^13^ In the other 2 RCTs, both of which compared single-port robot-assisted surgery to multi-port laparoscopic surgery, there was no significant difference in LOS.^15,16^ In general, patients across all the RCTs and observational studies were discharged within 1 to 2 days without a suggestive pattern favoring any particular procedure. There were no significant differences in total complications or surgical site infections between procedures, and most point estimates were on or extremely close to the null value of no difference. There was somewhat more variation in point estimates of differences in the 2 pain outcomes, but no clear pattern favoring 1 procedure over another. Twelve observational studies reported readmissions, and 4 of these studies demonstrated a significantly higher readmission rate in the laparoscopic surgery patients.^20,44,54,57^ Of those 4 studies, 1 had compared single-port robot-assisted cholecystectomy, multi-port robot-assisted cholecystectomy, and single-port laparoscopic cholecystectomy.^44^

Figure 3 Cholecystectomy Short-term Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted cholecystectomy and laparoscopic approach. RCTs are listed in the left-hand side, while observational studies are listed on the right-hand side.

Figure 4 presents graphically the results of the only long-term outcome, incisional hernia rates. This outcome is less frequently reported than the short-term outcomes and is included in only 2 RCTs^13,16^ and 10 observational studies.^23–25,27,30,32,36,39,41,51^ The 2 RCTs^13,16^ reported no statistically significant differences, but the 95% confidence intervals are very wide, and clinically important differences cannot be excluded. 3 observational studies^23,25,30^ found higher incisional hernia rates in the single-port robot-assisted cholecystectomy patients compared to the multi-port laparoscopic cholecystectomy patients. The point estimate of effect for these 3 observational studies is within the 95% confidence interval of the 1 RCT of this comparison,^16^ and in fact quite close to the RCT point estimate of effect. We interpret these findings as a possible signal that this long-term outcome may be worse in single-port robot-assisted cholecystectomy than multi-port laparoscopic cholecystectomy. In the remainder of the studies that reported on incisional hernia formation, there was no significant difference between robot-assisted cholecystectomy and laparoscopic cholecystectomy cohorts; 4 out of 6 of those studies compared single-port robot-assisted cholecystectomy to single-port laparoscopic cholecystectomy.

Figure 4 Cholecystectomy Long-term Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted cholecystectomy and laparoscopic approach. RCTs are listed in the left-hand side, while observational studies are listed on the right-hand side.

### Summary of Findings

In general, OR time was longer in patients treated with robot-assisted cholecystectomy compared to laparoscopic cholecystectomy. While not always statistically significant, data are consistent across RCTs and observational studies, and also consistent with differences in OR time seen between other robot-assisted procedures and their laparoscopic or open counterparts. There was no evidence of differences in total intraoperative complications in total intra-operative complications or conversions, and most studies had point estimates close to the null value. Only 5 studies reported common bile duct injuries, and there was no evidence of differences between robot-assisted cholecystectomy and laparoscopic cholecystectomy. There was no evidence across most studies of differences in LOS, post-operative complications, or SSI. Pain was reportedly inconsistently among the studies and there was no evidence favoring robot-assisted or laparoscopic surgery. The lack of difference in outcomes between techniques could in part be related to patient selection and the type of gallbladder pathology for which each technique was used. Additionally, studies capturing surgeons’ learning curve of the robot-assisted platform could factor in as well. The rate of incisional hernia may be higher in single-port robot-assisted cholecystectomy as compared to multi-port laparoscopic, a

All studies that demonstrated a statistically significant difference in incisional hernia rate compared single-port robot-assisted cholecystectomy to multi-port laparoscopic cholecystectomy. There was also no evidence of differences in the rate of incisional hernia rates for single-port robot-assisted and single-port laparoscopic cholecystectomy. This may be because the single-port approach with robot-assisted cholecystectomy or laparoscopic cholecystectomy involves a larger incision and confers a higher risk for developing an incisional hernia.

### Certainty of Evidence for Key Question 1A

We judged the certainty of evidence for most outcomes as being moderate, with evidence from RCTs and from observational studies mainly in agreement on the direction of effect. We judged the evidence for most outcomes as imprecise, leading to a reduction in the certainty of evidence (from high to moderate). OR time outcomes for robot-assisted compared to laparoscopic cholecystectomy was deemed moderate because of imprecision. We judged the results for intraoperative complications as moderate due to some imprecision, and common bile duct injury was considered low because of imprecision and sparsity of data. We judged the certainty of evidence for conversion rate between robot-assisted cholecystectomy and laparoscopic cholecystectomy as high, based on the RCT data. We judged LOS as imprecise but moderate, since 3RCTs reported this result. All postoperative complications and surgical site infection as moderate certainty of evidence due to imprecision. We judged the certainty of evidence for readmission outcome between robot-assisted cholecystectomy and laparoscopic cholecystectomy as low. We judged the certainty of evidence for pain as low due to inconsistent and imprecise results. Certainty of evidence for postoperative incisional hernia formation between robot-assisted cholecystectomy and laparoscopic cholecystectomy was deemed low due to inconsistency among the comparison groups and imprecision.

Table 1 Certainty of Evidence for Cholecystectomy Studies

Outcome | Study Limitations | Consistency | Directness | Precision | Certainty of Evidence
Intra-operative
OR Time; Robot > Laparoscopic | RCT: Low; Observational studies: High | Consistent | Direct | Imprecise | Moderate
Complications; Robot = Laparoscopic | RCT: Low; Observational studies: High | Consistent | Direct | Imprecise | Moderate
Common Bile Duct Injury; Robot = Laparoscopic | RCT: Low; Observational studies: Low | Consistent | Direct | Imprecise | Moderate
Conversions; Robot = Laparoscopic | RCT: Low; Observational studies: High | Consistent | Direct | Precise | High
Short-term Outcomes
Length of Stay; Robot = Laparoscopic | RCT: Low; Observational studies: High | Consistent | Direct | Imprecise | Moderate
Complications (total); Robot = Laparoscopic | RCT: Low; Observational studies: High | Consistent | Direct | Imprecise | Moderate
Surgical Site Infection; Robot = Laparoscopic | RCT: Low; Observational studies: High | Consistent | Direct | Imprecise | Moderate
Pain; Robot = Laparoscopic | RCT: Low; Observational studies: High | Inconsistent | Direct | Imprecise | Low
Readmissions; Robot < Laparoscopic | Observational studies: High | Consistent | Direct | Imprecise | Low
Long-term Outcomes
Incisional hernia; Single port robot > multiport laparoscopic | RCTs: Low; Observational studies: High | Inconsistent | Direct | Imprecise | Low

## KEY QUESTION 2A CHOLECYSTECTOMY: What is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic surgery for cholecystectomy?

Eighteen studies looked at robot-assisted cholecystectomy versus laparoscopic and included some measure of cost. There was 1 RCT.^13^ Of the remaining 17, the majority were retrospective, single institution, or single health system studies. There were 3 studies that used a national database^49,56,58^ and 1 study performed a budget impact analysis using existing published data.^59^ Studies were mixed with respect to procedures performed. Studies included a combination of traditional laparoscopic multi-port surgery, laparoscopic single-port surgery, robot-assisted multi-port surgery, and robot-assisted single-port surgery. Because most studies came from single institutions, sample sizes were generally small, with the majority of studies including fewer than 100 patients in the robot-assisted arm.

Overall, 16 of 18 studies reported at least 1 measure of cost higher for the robot-assisted surgery compared to the laparoscopic approach. The 1 RCT was a single institution study in Switzerland that evaluated 30 patients receiving single site robot-assisted surgery and compared them to 30 patients receiving single site laparoscopic surgery for elective cholecystectomy.^13^ They found nearly a 50% higher cost for the robot driven by higher consumable costs, amortization, and overhead costs (“the cost of OR time”).

Table 2 Evidence Table for Cholecystectomy Cost Studies

Author, Year, Number | Study Design, Number of Institutions | Comparison(s) | Number of surgeons | Sample Size | Source of cost data | Cost data | Misc. (Additional cost-pertinent outcomes and financial COI)
Bedeir 2016^60^ | Retrospective, single institution | Robot-assisted single site vs traditional laparoscopic for elective outpatient cholecystectomy | 1 (robot); 5 (lap) | 46 robot; 195 lap | “Cost data were obtained from financial department. Hospital cost in US dollars, not billed or hospital revenue. Cost divided into fixed and variable costs. Only variable costs are included. Fixed costs include salaries and hospital infrastructure. Fixed costs don’t differ between. procedures.” | Total median variable cost: 1319 (robot) vs 1737 (lap), p<0.001 | Provide OR time for robot but not for lap; One author had financial COI with Intuitive
Buzad 2013^33^ | Retrospective, single institution | Robot-assisted single incision vs historical control of laparoscopic single incision cholecystectomies | 1 | 20 robot; 10 lap | “Cost based on instrument cost from preference cards; did not include purchase price or maintenance of robot. Sensitivity analysis performed for instrument costs: SILC estimates were average cost, based on number of cases, and a theoretical range for single port. Theoretical savings of no cholangiogram for robot was calculated.” | Preference card cost for instruments = $1268 (robot) vs $1281 (lap); no p-value as these are just single values for the preference card; **Excluded cost of using 5 “reusable” robotic instruments** | Operative times 84 vs 85 min, p=NS; One author had financial COI with Intuitive
Farnsworth 2018^46^ | Retrospective, single institution; Abstract only | Robot-assisted vs laparoscopic acute care surgery cholecystectomy | 2 | 14 robot; 37 lap | “day of surgery until discharge” | Unadjusted OR costs: $3490 (robot) vs $2190 (lap), p<0.001; Adjusted analysis found robot was $980 more than lap BUT included OR time in analysis model | OR time 158 (robot) vs 132 (lap); P=NS; Financial COI not discussed
Grochola 2019^13^ | RCT, single institution | Robot-assisted vs laparoscopic single site elective cholecystectomy | 3 | 30 robot; 30 lap | “Costs generated in the operating theatre include consumables needed for dVSSC and SILS (each patient), non-procedure-specific surgical and anaesthesiologic consumables (costs per min), amortization of equipment and staff salaries (costs per minute). Ward costs divided into medical and non-medical expenses as overhead per min. | Total cost (in Swiss Francs): 9743 (robot) vs 6900 (lap), p=0.001; Driven by: Higher consumables (2921 vs 882, p<0.001), amortization (932 vs 493, p=0.02), overhead costs in OR (1933 vs 1555, p=.017) | Total operative duration: 85.5 (robot) vs 74 (lap), p=NS; Authors declared no conflicts
Gustafson, 2016^36^ | Retrospective, single institution | Robot-assisted single-incision laparoscopic cholecystectomy (RSILC) vs traditional single incision laparoscopic cholecystectomy (TSILC) | 1 | 38 robot; 44 lap | “Operative costs were obtained from the hospital database” | Variable direct supply cost ($1,967 robot vs $1,969 lap, p=0.99); Variable direct labor cost ($1,234 robot vs $1,122 lap, p=0.34).; Fixed direct cost:$8,961 robot vs $5,379 lap, p<0.0001; Mean service item charges (not defined):$14,594 robot vs $9,347 lap, p<0.0001).; Total cost: $8,961.00 robot vs $5,379.00 lap | OR time 98 robot vs 68 lap, p<0.0001; Authors declared no conflicts
Hagen 201 8^25^ | Retrospective, single institution | Robot-assisted single site vs lap multi-port | Did not specify | 99 robot; 99 lap (matched analysis) | “Cost of the primary procedure was calculated including the capital investment and maintenance of robot with a flat fee per case as per hospital, instruments, and accessories per standardized OR procedure set, cost per OR-time of 17.3 USD per min in OR, and cost of hospitalization USD 627 for outpatients, and USD 1425 per day for inpatients as either previously established or per guidance of medical controlling department.” | Total cost of index procedure $6158 (robot) vs $4288 (lap), p<0.0001; In addition: cost of follow-up surgery was $695 (robot) vs $0 (lap), p=0.02 | Operative time: 97 min (robot) vs 94 min (lap), P=NS; Incisional hernia requiring surgery rate: 7% (robot) vs 0% (lap), p=0.014; Author financial COI with Intuitive
Hawasli, 2016^55^ | Retrospective, single institution | Robot-assisted cholecystectomy (14/26 with single incision RC, all included in 1 analysis) vs laparoscopic cholecystectomy (26/220 with single incision LC, all included in 1 analysis) | 14 | 26 robot; 220 lap | No discussion of cost methods | Mean direct cost: ($2,704.08 RC vs $1,712.50 LC, p<0.0001); Gross median margin w/ no difference ($1,726 LC vs $1,593 RC) | Mean case time RC: 121min vs LC: 98.4min, p<0.001; Mean OR time: RC: 86.6min vs LC: 63.9 min; Financial COI not discussed
Higgins 2016^61^ | Retrospective, single “health system” | Elective robot-assisted vs laparoscopic cholecystectomy | Did not specify | 39 robot; 343 lap | **See Footnote 1** | Total supply cost: $1699 (robot) vs $631 (lap), p<0.01 | Case duration: 84 min (robotic) vs 76 min (lap), p=NS; Authors had no financial ties to Intuitive
Kaminski 2014^58^ | Retrospective, National Inpatient Sample (2010-2011) | Robot-assisted vs laparoscopic cholecystectomy for gallstone disease | Did not specify | 524 + 1084 (robot, 2010/2011); 362,971 + 370,958 (lap, 2010/2011) | “NIS data include total charges for individual hospitalizations. HCUP provides cost-to-charge ratios, to convert charges to estimated hospital costs. Costs calculated as product of total charges and cost-to-charge ratio. Hospital costs reflect money expended for patient care (not physician expenses). Indirect (non-medical) costs were not available. NIS data don’t allow calculating attributable costs.” | Total costs:; $21346 (robot) vs $13829 (lap) in 2010, p<0.05; $18224 (robot) vs $14181 (lap) in 2011, p<0.05 | Authors declared no conflicts
Kane 2020^57^ | Retrospective, Single Institution | Robot-assisted vs laparoscopic cholecystectomy | 2 | 106 robot,; 1060 lap | “Financial data were obtained from the Institutional Clinical Data Repository; Inflation estimates of the Center for Medicare and Medicaid Services Inpatient Prospective Payment System were used to adjust cost to 2017 US dollars to account for medical-specific inflation.” | Hospital cost:; $6611 (robot) vs $4930 (lap), p<0. 0001 | Total OR time 185 min (robot) vs 160 min (lap), p<0.001; Authors declared no conflicts
Khorgami 2019^49^ | Retrospective, National Inpatient Sample (2012-2014) | Robot-assisted vs laparoscopic cholecystectomy | Did not specify | 1271 robot; 69,402 lap | “Hospital total charges were converted to cost estimates using hospital specific cost-to-charge ratios provided by HCUP. Average total cost of hospitalization was compared for the LS and RAS cohorts. Difference between average costs of laparoscopic vs robotic were calculated for each surgical subgroup.” | $10,944 (robot) vs $9618 (lap), “statistically significant”, no p-value provided | Authors declared no conflicts
Lescouflair 2014^42^ | Retrospective, single institution; Abstract only | Robot-assisted single incision laparoscopic cholecystectomy (RSILC) vs single incision laparoscopic cholecystectomy (SILC) | 1 | 41 RSILC; 41 SILC | “Outcomes and cost were compared between the 2 groups.”; “Secondary outcomes include duration of narcotic use, time to independent performance of daily activities and cost.” | Cost: $3,673 SILC vs $7,518 RSILC, p=0.056 | OR time (min): RSILC 96.7 vs SILC 65.2 min, p<.00001; Conflicts not reported
Li, 2017^28^\| | Retrospective, single institution | Single-site RC vs conventional LC (Number of ports not specified) | 2 | 78 robot; 367 lap | “Assessed data of total operation time, length of hospital stay, hospital charge, outpatient department (OPD) visits after discharge, and OPD service charges.” | Results in New Taiwan Dollars:; Average hospital charge: RC: 204,125 vs LC: 49,218, p=0.001; Average OPD charge: RC: 836.6 vs 509.6, p=0.001 | OR time higher for RC (RC: 75.7 min vs 64.37 min, p=0.035); Authors declared no conflicts
Morris 2014^59^ | Budget impact model for the UK NHS; Abstract only | Robot-assisted vs laparoscopic cholecystectomy | NA | NA | “A model-based economic evaluation investigating cost of procedure accounting for operating staff, assistant time, theatre time, laparoscopic and robotic systems, instruments and LOS. Data from published sources.” | Lap 2703 pounds vs robot 2877-15,253 pounds depending on service life and number of procedures per year | Conflicts not reported
Newman 2016^62^ | Retrospective, single institution | Traditional lap vs single site lap vs single site robot-assisted | Did not specify | 39 robot; 11 single lap; 50 traditional lap | **See Footnote 2** | “Direct variable surgeon cost”: traditional lap $929 Single incision lap $1407; Robotic $2608 (all comparisons p<0.05) | Exact values not provided for OR time, ~ 65-75 for traditional, ~ 75-110 for single incision lap, ~ 90-105 for robot; Authors declared no conflicts
Pokala 2019^56^ | Retrospective, Vizient national database | Lap vs robot-assisted cholecystectomy for minor or moderate severity of illness | Did not specify | 1,314 robot; 53,028 lap | “Ratio of cost-to-charge (RCC) methodology is applied to estimate the cost of patient care along service lines” | Total cost: $8620 (robot) vs $6503 (lap), p<0.001 | LOS: 3.27 (robot) vs 3.1 (lap), p<0.001; One author had financial COI with a robotic surgical company
Rosemurgy, 2014^50^ | Retrospective, single institution | Laparoscopic vs Robot-assisted Cholecystectomy (did not specify how many incisions) | Did not specify | 31 robot 201 lap | “Through the Decision Support Team, … Hospital Charges, Hospital Cost, Net Revenue, earnings before depreciation, interest, and taxes (EBDIT), and Net Income. Hospital Charges were the value requested for reimbursement. Hospital Cost was the value of money used to produce care described. Net Revenue defined as money received, regardless of cost of operation. EBDIT defined as Net Income before depreciation, interest, and income taxes. Net Income is value after Hospital Cost has been applied to Net Revenue. Hospital Cost data were subdivided into variable costs, fixed costs, supply costs, drug costs, equipment costs, and facility costs. Fixed costs were defined as expenses that were not dependent on the level of care provided by the hospital. Facility Costs included basic Hospital Costs which cannot be traced to individual patient care and are, rather, allocated to all patients adjusted for severity of intervention and illness. | Charges RC $33,238.42 vs LC $25,055.85, p<0.01; Net revenue: RC $9,121.49 vs LC $6,512.61, p = 0.29; EBDIT: RC $6,196.07 vs LC $3,507.86, p=0.26; Net income: RC $5,848.59 vs LC $3,058.83, p=0.25; Variable costs : RC $1,714.30 vs LC $1,449.54, p=0.022; Fixed costs: RC $1,826.90 vs $1,915.93, p=0.1665; Supply costs: RC $594.74 vs LC $636.65, p=0.4191; Drug costs: RC $92.91 vs LC $76.93, p=0.5575; Equipment costs RC $336.96 vs LC $345.14, p=0.5076; Facility costs: RC $22.60 vs LC $22.71, p=0.3099; Total costs: RC $4,723.26 vs $4,578.88, p=0.7265 | Operative duration RC 140 vs Lap 93, p<0.01); No authors had financial ties to Intuitive
Strosberg, 2017^51^ | Retrospective, single institution | Robot-assisted vs laparoscopic cholecystectomy (did not specify how many incisions) | 1 | 97 lap (total); 140 robot (total); 35 lap (cost analysis); 68 robot (cost analysis); *Patients that had IOC, conversion to open or did not have a payment were excluded from cost analysis | “Cost data was obtained for each patient in the study group by our institution’s financial division. Variables including total charges, total payments, total direct cost, total indirect cost, and total overall cost were collected. Direct cost defined as the sum of operative and hospital cost. Revenue was calculated as total payments minus total overall cost. Exclusion for cost analysis included cases with uncaptured operative and in-hospital payments, inpatient procedures, and cases with intraoperative cholangiogram or conversion to open.” | Total charges: RC $33,120 vs $21,024, p<0.01; Total payments: RC $7,478 vs $5,887, p=0.34; Total direct cost: RC $4,692 vs $2,983, p<0.01; Total indirect cost: RC ($4,243 vs $2,801, p<0.01; Total cost: RC $8,870 vs $5,771, p<0.01; Median revenue: RC - 848 vs 186, p<0.01 | Length of surgery longer for RC (74.5min vs 56min, p<0.01)

Footnote 1 “All data were obtained from the Surgical Profitability Compass Procedure Cost Manager System. Outcomes measured: LOS, case duration, and total supply cost. Total supply cost accounted for the cost of mesh. For robotic cases, total number and cost of robotic instruments were determined. Cost accounting for robotic instruments is determined by the purchase price of a particular instrument distributed equally among all the patients in whom the instrument was used.”

Footnote 2 “We developed mechanics that could identify the portion of procedure cost under control of the surgeon. This was defined as direct variable surgeon cost (DVSC): surgical supply cost (drapes, gloves, etc); physician preference items; technology cost (per-use laparoscope cost, service contract amortized); and procedure time cost was variable cost of operating room use: 2.5 full-time equivalents per case minute. Proprietary robotic instruments are disposable after a pre-programmed number of uses, 5 or 10. Total cost of instrument divided by intended number of uses as each case cost: not corrected for actual number of uses.”

Many of the studies had significant limitations, primarily related to the measurement of costs. Studies varied in terms of the detail provided as it relates to cost, with some providing no information at all. Others provided more specifics but only looked at 1 component of cost, such as disposable supply costs. Given the upfront cost of the robot, including the purchase price and ongoing maintenance costs, these cost assessments are incomplete. Studies also varied in their use of charges, payments, and costs, each of which will be more relevant to different parties. Charges, for example, are rarely paid by insurers and do not necessarily reflect the resources expended to care for the patient. Using cost-to-charge ratios to convert charges to costs is a blunt measure that is likely inaccurate, especially in surgery.^11^ Even among studies that focused on hospital costs, whether they included staff costs or indirect costs varied from 1 study to the next and these details were often not explicitly mentioned. As a result, cost estimates varied markedly across studies from as low as $1400 to as high as $33K. No study commented on updating costs based on inflation nor did they reference any type of recognized methodology when reporting cost information (eg, Second Panel on Cost Effectiveness, CHEERS).

### Summary of Findings

While there are a number of studies comparing robot-assisted versus laparoscopic surgery for cholecystectomy, all had significant limitations, primarily surrounding the cost methodology used (or lack of methodology). Nevertheless, there was an almost unanimous finding, including in randomized data, that the robot-assisted approach is more expensive than laparoscopic.

### Certainty of Evidence for Key Question 2A

Despite wide heterogeneous methodologic approaches to assessing cost in these studies and differing definitions of cost, nearly all found that robot-assisted approach for cholecystectomy was more expensive than laparoscopic. This directness and consistency support that that we have moderate certainty that robot-assisted is more expensive than laparoscopic cholecystectomy. How much more expensive is not known with precision.

## KEY QUESTION 1B INGUINAL HERNIA SURGERY: What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for inguinal hernia repair?

We identified 23 publications that met inclusion criteria. There was 1 RCT, which was a US multi-institutional study of 102 patients assessing short-term outcomes between robot-assisted and laparoscopic unilateral inguinal hernia repair.^63^ The remaining 22 studies were observational. Of these, 16 specified laterality in the patient demographics.^64–79^ 4 studies reported on unilateral inguinal hernia only, ^64,68,71,75^ while 12 reported on both unilateral and bilateral.^65–67,69,70,72–74,76–79^ The robot-assisted approach was compared to the laparoscopic approach in 18 studies.^12,64,65,68,70–83^ Similarly, the open approach was compared to robot-assisted in 14 studies.^12,66–72,77,79,80,82–84^ 8 studies included primary and recurrent hernias.^67,69,70,73–76,78^ Of the remaining 14 studies, 5 reported only on primary hernias^68,71,79,80,84^ and the other 9 did not specify.^12,64–66,72,77,81–83^ Two studies were performed outside of the US.^72,73^ Also, 3 studies reported outcomes from patients who were served at the Veterans Affairs hospital system.^67,68,70^ 8 studies utilized prospectively maintained datasets.^64,68,,71,73,77,80,82,84^ The studies varied in size from 55 to 75,981 patients. Propensity matching was performed in 5 studies.^12,66,69,77,83^ Of note, 2 studies published by the same group utilized overlapping patient samples,^66,69^ of which 1 study only examines the outcomes for the subgroup of patients who are obese.^66^ Thus, only the study assessing the broader subset of patients is plotted in the subsequent figures.^69^

Intraoperative outcomes included OR time and rate of conversion from robot-assisted or laparoscopic surgery to open (Figure 5). Of the 8 studies included in this analysis, 5 compared robot versus laparoscopic approach, and 4 compared robot to open approach.^65,67–69,73–75,78^ With 2 exceptions, all studies found that OR time was longer for the robot-assisted approach compared to either the laparoscopic approach or the open approach. One study reported similar increased OR time with unilateral laparoscopic robot-assisted inguinal hernia repair compared to robot-assisted laparoscopic surgery.^67^ However, there was no evidence of differences between the 2 approaches for bilateral inguinal hernia repair. Another study assessed the learning curve of an experienced surgeon and found length of OR time decreased with experience and was not different at the end of the study.^74^ There was no evidence of differences in conversions between robot-assisted and laparoscopic approaches.

Figure 5 Inguinal Hernia Intraoperative Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted inguinal hernia repair and either laparoscopic (green) or open (gold) approaches.

Four postoperative short-term (≤30 days) outcomes were assessed for inguinal hernia repair: LOS, surgical site infections (SSI), readmissions, and total complications (Figure 6). Of the 5 studies assessing outcomes for LOS,^65,69,75,77,78^ 2 studies demonstrated significantly decreased inpatient LOS for robot-assisted inguinal hernia repair compared to open approach,^69,77^ and 1 of these studies^77^ demonstrated significantly decreased inpatient LOS for robot-assisted repair compared to laparoscopy as well. We elected to only graph the outpatient LOS in the corresponding figure, for which there was no difference among the 3 approaches, as this represents the more common disposition for this surgery. Two studies that looked at unilateral repairs did not show a difference between robot-assisted and laparoscopic approaches.^75,78^ The final study reported outcomes for both unilateral and bilateral repairs, and they also found no difference in LOS for robot-assisted versus laparoscopic approach.^65^

Of the 7 studies assessing outcomes for SSI,^63,64,67–69,74,78^ the RCT reported a trend to lower SSI rate when comparing robot-assisted to laparoscopic surgery,^63^ and 2 studies reported a trend to lower SSI rate in robot-assisted surgery compared to open,^67,69^ but none of these studies met statistical significance (Figure 6). In contrast, 2 studies reported a non-significant trend to higher SSI rate in robot-assisted surgery compared to laparoscopic and open surgery.^68,78^ The 2 remaining studies did not report a significant difference in SSI rates between robot-assisted versus laparoscopic approaches.

Five studies assessed outcomes for readmission following inguinal hernia repair.^64,68,69,74,78^ One study that compared all 3 approaches for unilateral hernias found that readmission rates were lower for robot-assisted as compared to either laparoscopic or open approaches.^68^ The remaining 4 studies did not find a significant difference in readmission rates: 3 assessed robot versus laparoscopic repair (unilateral and a mix of laterality),^64,74,78^ and 1 assessed robot versus open (for mix of laterality).^69^

Nine studies assessed outcomes for total complications.^63,64,67–69,71,73,74,78^ Only 1 observational study found lower complication rates for the robot-assisted approach, which was seen in both the laparoscopic and open comparative arms.^71^ Of note, this study looked at only unilateral hernia repair. The remaining 10 studies, including the RCT, did not demonstrate significant differences in complications by approach: 6 studies assessed robot-assisted compared to laparoscopic approach (4 of which were on unilateral and 2 were mixed laterality)^63,64,68,74,75,78^ and 4 assessed robot-assisted to open repair (2 on unilateral hernias, 1 on bilateral hernias, and 3 on a mix of laterality^67–69,73^).

Figure 6 Inguinal Hernia Postoperative Short-term Outcomes

Figure 6 footnote: Only outpatient LOS was plotted for the LOS outcome.

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted inguinal hernia repair and either laparoscopic (green) or open (gold) approaches.

For long-term outcomes, 5 studies assessed inguinal hernia recurrence (Figure 7).^64,67,68,71,80^ One study demonstrated lower recurrence rate for the robot-assisted approach as compared to both laparoscopic and open repair (for unilateral hernia repair).^71^ Two did not demonstrate a statistically significant difference that assessed both robot-assisted to laparoscopic and open comparative arms.^68,80^ Two additional studies also didn’t show differences in recurrence rates: 1 assessed robot-assisted to laparoscopic comparing unilateral hernia repairs,^64^ and another study comparing a mix of hernia laterality for robot to open repair.^67^

Figure 7 Inguinal Hernia Postoperative Long-term Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted inguinal hernia repair and either laparoscopic (green) or open (gold) approaches.

Six studies assessed postoperative pain following inguinal hernia repair (Figure 8).^63–65,67,73,79^ The RCT did not show a significant difference in pain outcomes for robot-assisted compared to laparoscopic inguinal hernia repair.^63^ One observational study reported worse pain for the robot-assisted approach as compared to open repair for a mix of hernia laterality.^73^ The remaining observational studies did not demonstrate a significant difference in pain among robot-assisted, laparoscopic, and open inguinal hernia repair for unilateral, bilateral, and mixed laterality repairs.

Figure 8 Inguinal Hernia Postoperative Pain Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted inguinal hernia repair and either laparoscopic (green) or open (gold) approaches.

### Summary of Findings

Operative room time was longer in patients treated with robot-assisted inguinal hernia repair compared to laparoscopic or open repair, particularly for unilateral hernia. There were no differences in conversions between robot-assisted and laparoscopic approaches. In terms of LOS, there may be a signal of a small benefit favoring the robot-assisted approach compared to open surgery for inpatient stays, but no difference for outpatient surgeries, which is the more common practice. There does not appear to be a signal of benefit with regard to SSI for the robot-assisted approach compared to laparoscopic or open surgery. There may be a small signal of benefit for lower readmissions with the robot-assisted approach for unilateral hernias. Regarding total short-term postoperative complications and hernia recurrences, there is minimal to no benefit of the robot-assisted approach for inguinal hernia repair compared to the laparoscopic or open approaches. Most studies demonstrated no difference among approaches when assessing postoperative pain.

### Certainty of Evidence for Key Question 1B

Only 1 RCT was included in our analysis, for which there was greater certainty of evidence; however, it was judged as having moderate study limitation due to its single-blinded design with unclear allocation concealment and blinding of outcome assessment and potential for author bias. Due the observational nature of all remaining eligible studies, the study limitations were high and certainty of evidence was subsequently lower. We judged the certainty of evidence for the outcomes of longer OR time for robot-assisted inguinal hernia repair compared to laparoscopic and open inguinal hernia repair as low, primarily because data was imprecise. We judged the certainty of evidence that LOS for inpatient stays following robot-assisted surgery is shorter compared to open repair and no difference in outpatient LOS as moderate. Evidence that LOS for robot-assisted was not different compared to laparoscopic repair was determined to be moderate. We judged the certainty of evidence that SSI rates following robot-assisted surgery were not different as compared to laparoscopic and open repair as low due to inconsistency and imprecision of the data. We deemed certainty of evidence that readmissions following robot-assisted surgery were similar to the other 2 approaches as low based on inconsistency in the data. The evidence of no difference in major complications and recurrences among the surgical techniques was assessed as very low due to inconsistency and imprecision of the data. The certainty of evidence that there is no difference in postoperative pain among the 3 approaches was judged as low due to inconsistency and imprecision.

Table 3 Certainty of Evidence for Inguinal Hernia Repair Studies

Outcome | Study Limitations | Consistency | Directness | Precision | Certainty of Evidence
Intraoperative
Operating Room Time; Robot > Open/Laparoscopic | Observational studies: High | Consistent | Direct | Imprecise | Moderate
Postoperative Short-Term Outcomes
Length of Stay; Robot <Open (inpatient) | Observational studies: High | Consistent; Consistent | Direct; Direct | Precise; Precise | Moderate; Moderate
Robot = Open (outpatient); Robot = Laparoscopic | | Consistent | Direct | Precise | Moderate
Surgical Site Infection; Robot = Open/Laparoscopic | RCT: Moderate; Observational studies: High | Inconsistent | Direct | Imprecise | Low
Readmissions; Robot = Open/Laparoscopic | Observational studies: High | Consistent | Direct | Imprecise | Low
Total complications; Robot = Open/Laparoscopic | RCT: Moderate; Observational studies: High | Inconsistent | Direct | Imprecise | Low
Postoperative Long-Term Outcomes
Hernia Recurrence; Robot = Open/Laparoscopic | Observational studies: High | Consistent | Direct | Imprecise | Very Low
Pain; Robot = Open/Laparoscopic | RCT : Moderate; Observational studies: High | Inconsistent | Direct | Imprecise | Low

## KEY QUESTION 2B INGUINAL HERNIA SURGERY: What is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for inguinal hernia repair?

There were 5 studies that reported cost information for inguinal hernia repairs. There was 1 RCT.^63^ Of the remaining 4 studies, 3 were single-institution retrospective reviews^65,68,78^ and the last was a retrospective review of a national database.^77^ The 1 randomized trial compared robot-assisted and laparoscopic transabdominal hernia repairs at 6 institutions in the United States. They limited inclusion to only surgeons who had performed at least 25 prior robot-assisted and laparoscopic procedures. With respect to cost, they found the robot-assisted approach had over twice the hospital cost of the laparoscopic approach ($3,258 vs $1,421). They did not include capital equipment costs in their analysis.

Three of the 4 remaining studies also found the cost of the robot-assisted approach to be higher than the cost of the laparoscopic approach. Details regarding what went into cost estimates were generally limited. One study did not mention any information aside from “financial data were obtained from the institutional Clinical Data Repository.” The 1 study that did not find a cost difference excluded a large component of robot-assisted costs (purchase price of equipment and annual contract),^2^ likely accounting for their null findings. None of the studies comment on how they accounted for staff/labor costs, which are the largest component of OR costs.^10^ This point is important as all 4 that reported operative time found operative time to be longer in the robot-assisted arm compared to the comparison arms. None of the studies reference a recognized methodology when reporting cost information (eg, Second Panel on Cost Effectiveness, CHEERS).

Table 4 Evidence Table for Inguinal Hernia Cost Studies

Author, Year, Number | Study Design, Number of Institutions | Comparison(s) | Number of surgeons | Sample Size | Source of cost data | Cost data | Misc. outcomes
Charles, 2017^68^ | Retrospective review, single institution | Robot-assisted vs lap vs open primary unilateral inguinal hernias | 10 | 69 robot; 241 lap; 191 open | “Financial data were obtained from the institutional Clinical Data Repository.” | Hospital cost: Robot $7162, lap $4527, open $4264 (p<0.001) | OR time longer for robotic surgery (105 min robot, 81 min lap, 71 min open; p<0.001); No difference discharge home same day
Janjua 2020^77^ | Retrospective, HCUP-State Inpatient Databases & AHA data from 8 states (2009-2015) | Robot-assisted vs lap vs open inguinal hernia repairs for inpatients | Not stated | 2960 (open), 2960 (lap), 1480 (robot); propensity matched | “HCUP-provided cost-to-charge ratios were used to calculate cost by multiplying total charges with cost-to-charge ratio. For dataset containing cost, years 2011 - 2014 for Iowa were dropped because no cost data was available.” | $18,494 (robot) vs $14,738 (lap) vs $16,740 (open); p<0.0001 for robot vs open and lap comparisons | LOS: 5.0 (open), 3.6 (lap), 2.2 (robot); p<0.0001 for robot vs open and lap comparisons
Khoraki 2019^78^ | Retrospective, single institution | Robot-assisted vs lap inguinal hernia repair | 4 | 45 (robot); 138 (lap) | See footnote 1 | Total hospital cost: $9994 (robot) vs $5995 (lap), p<0.01 | Operative time: 116 min (robotic) vs 95 in (lap), p<0.01
Prabhu 2020^63^ | Multi-institutional RCT | Robot-assisted vs lap TAPP | Not stated | 54 lap; 48 robot | Costs per case at each institution were reported as total cost, operating room cost (cost per min OR time per case), and disposable/reusable cost, include disposable materials and reusable materials - robotic instruments. Robotic and laparoscopic capital equipment cost were not amortized. | Total cost $3258 (robot) vs $1421 (lap); p<0.001 | Operative time (skin to skin) 75.5 min (robot) vs 40.5 min (lap), p<0.001
Waite, 2015^65^ | Retrospective, single institution | Robot-assisted vs laparoscopic TAPP repair | Not stated | 24 lap; 39 robotic | “institution financial department… included direct costs, facility net revenue, and contribution margin”; Direct costs were variable costs of surgery (ie, mesh, disposable lap equipment, reposable robotic equipment). Capital costs (ie, robotic system, lap towers, and non-disposable equipment) NOT included. | Average direct cost per case was $3216 (lap) vs $3479 (robot), p=NS | Operative time was longer robotic (77.5 minutes vs 60.7 minutes, p=0.001)

Footnote 1 3 separate cost analyses were performed: 1. Total hospital costs: estimated cost of anesthesia, operating room, and recovery in addition to the disposable supplies and medications used during surgery. A combination of case-level and time-based system (per 1/2 h increment) used to calculate cost of surgery. Case-level is determined by ASA, procedure complexity, and equipment and staff. 2. Total disposable supplies and categories costs: combined operating room usage with supply pricing. Each surgery had its disposable supplies usage queried. Amount and costs for trocars, fixation devices, meshes, medications, drapes, and all accessories and other disposable equipment were collected. Cost adjusted to 2017 dollars. 3. Capital and service cost of the Robotic da Vinci® Surgical Systems: actual cost of systems was obtained and its depreciation was calculated based on an estimated 6-year lifespan. Capital cost associated with utilizing the robot per case was calculated as total depreciation during the study period divided by number all robotic cases performed by all surgeons. Cost of maintenance services per case was added.

### Summary of Findings

Five studies compared the costs of robot-assisted as compared to laparoscopic or open surgery for inguinal hernia repair. While there were significant limitations with the methodology, there is a consistent finding, including from randomized data, that the robot-assisted approach is more expensive than the laparoscopic and the open approach. How much more expensive is not known with precision. However, the lack of cost-effectiveness studies suggests that weighing the balance between the added cost against possible benefits and risks of the robot-assisted approach are not known.

### Certainty of Evidence for Key Question 2B

Based on directness and consistency in the evidence, including from randomized data, we have moderate certainty that robot-assisted surgery is more expensive than laparoscopic or open surgery for inguinal hernia repair. As there were no formal cost-effectiveness analysis, no conclusion can be made in that regard.

## KEY QUESTION 1C VENTRAL HERNIA SURGERY: What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for ventral hernia repair?

We identified 21 publications that met the inclusion criteria for assessing clinical outcomes. There was only 1 RCT, which was a conference abstract comparing robot-assisted to laparoscopic ventral hernia repair.^85^ The remaining 20 studies were observational studies, of which 7 studies compared robot-assisted ventral hernia repair to open repair only,^86–92^ 11 studies compared robot-assisted surgery to laparoscopic surgery only,^76,93–102^ and 2 studies compared robot-assisted surgery to both laparoscopic and open approaches.^103,104^ Six studies included analysis of patients who underwent transversus abdominis release as a component of the ventral hernia repair.^86–88,90,92,101^ The only RCT was a single institutional study from Brazil and included 38 subjects.^85^ All of the observational studies were done in the United States; of these, only 4 were specified to be multi-institutional,^87,90,96,97^ while 9 were specified to be from a single institution.^76,86,88,92,93,95,100–102^ Eleven of the observational studies utilized retrospective data from prospectively maintained databases.^89–92,94,96,98,99,101,103,104^ The studies varied in size from 25 to 46,799 subjects. Of the observational studies, 7 studies utilized matching of various preoperative patient or hernia characteristics in their outcome analysis.^87,89,90,96,97,99,103^

The RCT warrants specific mention.^85^ It was very limited in terms of the data the authors presented and was only an abstract. The sample sizes were quite small, 19 in each arm. The study compared robot-assisted ventral hernia to laparoscopic, but other details of the operative techniques were not provided. They did not report on our intraoperative outcomes of interest (OR time, intraoperative complications, transfusions, or conversion to open surgery) or the majority of our postoperative short-term outcomes (LOS, complications, SSI, or readmissions). They did report (without actual supporting data) that “QOL before and after the procedures showed improvement in both groups and but in favor of the robot-assisted group as well as the gain in the abdominal wall function.” They reported lower recurrence rate for robot group, 10.5% (2/19) as compared to 21.1% (4/19) at 1 year. One death was reported in the laparoscopic group. They did not comment on any deaths in the robot-assisted group. Therefore, this RCT was not abstracted along with the observational data analyzed below.

Figure 9 presents results for 4 intraoperative outcomes: OR time, intraoperative complications, transfusions, and conversion to open surgery. Fourteen observational studies were included in this subset of analysis.^76,86–88,90–93,95–97,100,101,103^ One study compares robot-assisted surgery to both laparoscopic and open approaches,^103^ while 7 studies only compare to laparoscopic,^76,93,95–97,100,101^ and 6 studies only compare to open surgery.^86–88,90–92^ Four studies^87,90,96,103^ utilize preoperative patient characteristics for matching, while the remaining 8 do not utilize matching.

Of the 11 studies assessing OR time, all studies demonstrate a statistically significant increase with robot-assisted ventral hernia repair compared to open and laparoscopic approaches,^76,86–88,93,95,97,100,101,103^ with the exception of 1 study that demonstrated no difference comparing robot to open repair.^92^ Of the 7 studies assessing intraoperative complications,^86,87,90,91,96,101,103^ 2 unmatched studies demonstrate a significantly decreased complication rate with robot-assisted ventral hernia repair compared to laparoscopic and open repairs,^86,101^ and the remaining unmatched study demonstrated no difference in complication rate between robot-assisted and open repair.^91^ The 4 matched studies do not demonstrate a significant difference in complication rate among the approaches.^87,90,96,103^ Two matched studies were included in the analysis for transfusion,^96,103^ of which 1 study demonstrated a significant decrease in transfusions in robot-assisted ventral hernia repair compared to both open and laparoscopic approaches,^103^ while the other study did not demonstrate a difference between robot-assisted and laparoscopic surgeries.^96^ Of the 6 studies included in the analysis for conversion,^86,90,92,95,101,103^ 1 matched^103^ and 1 unmatched^101^ study each demonstrated a decreased conversion rate to open surgery with robot-assisted surgery compared to laparoscopy, while a third study^95^ favored decreased conversion rates with robot-assisted surgery but was not significant. Of the 4 studies assessing robot-assisted conversion rates when compared to open ventral hernia repair, 1 matched study showed a significantly increased conversion rate of robot-assisted surgery,^90^ while another matched study demonstrated a non-significant increase in conversion.^103^ Of the remaining 2 unmatched studies, 1 showed a non-significant increase in conversion from robot-assisted surgery to open,^92^ while there was no difference in the remaining study.^86^

Figure 9 Ventral Hernia Intraoperative Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted ventral hernia repair and either laparoscopic (green) or open (gold) approaches. Studies utilizing matching (circles) are listed in the left-hand side, while studies that did not utilize matching (squares) are listed on the right-hand side.

Figure 10 presents the results for 5 postoperative short-term outcomes: LOS, complications, surgical site infection (SSI), readmissions, and mortality. Nineteen observational studies were included in this subset of analysis.^76,86–88,90–104^ Two studies compared robot-assisted surgery to both open and laparoscopic approaches,^103,104^ 11 studies compared to only laparoscopy,^76,93–102^ and 6 studies compared to only open surgery.^86–88,90–92^ Five studies^87,90,96,99,103^ utilized matching while the remaining 14 did not.

Of the 18 studies assessing outcomes for LOS,^76,86,87,90–104^ 6 studies comparing the robot-assisted to laparoscopic approaches,^76,96,99,101,102,104^ of which 2 were matched,^99,105^ demonstrated a significantly lower LOS for the robot-assisted arm. All 7 studies comparing robot-assisted ventral hernia repair to the open approach,^86,87,90–92,103,104^ of which 3 were matched,^87,90,103^ also demonstrated a significantly lower LOS. Within the matched cohort, only the laparoscopic comparison arm of 1 study demonstrated no difference in LOS.^103^ In contrast, 1 unmatched study demonstrated a small but statistically significant increase in LOS with robot-assisted surgery compared to laparoscopy.^97^ However, the remaining 5 studies did not demonstrate a significant difference.^93–95,98,100^

Of the 13 studies assessing outcomes for complications,^87,90,92,93,95–101,103,104^ 4 matched studies revealed a significantly lower rate of postoperative complications of robot-assisted ventral hernia repair compared to both laparoscopic and open approaches,^87,96,99,103^ and 1 unmatched study demonstrated a lower robot-assisted complication rate compared to laparoscopy.^93^ Only 1 matched study demonstrated a non-significant trend toward lower complication rates in the robot-assisted arm compared to open surgery.^90^ In 1 unmatched study, robot-assisted ventral hernia repair demonstrated a slight but significant decrease in complication rate compared to the open approach, while within the same study, the robot-assisted surgery demonstrated a similarly slight but significant increase in complications when compared to laparoscopy.^104^ The remaining 6 studies demonstrated no difference in complication rate in robot-assisted ventral hernia repair compared to laparoscopy or open surgery.^86,92,95,98,100,101^

Of the 9 studies examining the outcome of SSI,^86,87,91,95–97,100,101,103^ only 1 matched study^87^ demonstrated a significantly lower SSI rate with robot-assisted surgery compared to open repair. In a matched study comparing robot-assisted ventral hernia repair to both open and laparoscopic approaches, there was a trend toward lower SSI with robot-assisted surgery when compared to open surgery, but there was no difference when compared to laparoscopic repair.^103^ The remaining 7 studies did not demonstrate a significant difference among the approaches in SSI rates.^86,91,95–97,100,101^

Of the 11 studies assessing outcomes for readmissions,^86–88,90–93,96,99,101,104^ 1 unmatched study demonstrated significant decrease in readmission rate following robot-assisted ventral hernia repair compared to open.^92^ Two other unmatched studies demonstrated non-significant decreases in readmission following robot-assisted surgery compared to open.^88,91^ The remaining 4 studies comparing robot-assisted to open surgery^86,87,90,104^ including 2 matched studies,^87,90^ demonstrated no difference. There was no difference in readmission rate in the 5 studies comparing robot-assisted ventral hernia repair to laparoscopy,^93,96,99,101,104^ of which 2 were matched.^96,99^

Of the 8 studies assessing mortality, the data was overall mixed with none of the studies demonstrating significantly different mortality rates among the approaches.^86,87,90,95,96,98,101,104^

While 1 matched^90^ and 1 unmatched^104^ study demonstrate non-significant trends toward decreased mortality rates with the robot-assisted approach when compared to open surgery, another pair of matched^87^ and unmatched^86^ studies showed no difference in mortality between these approaches. When comparing robot-assisted ventral hernia repair with the laparoscopic approach, 2 studies,^96,104^ of which 1 was matched,^96^ had a trend toward increased mortality with robot, while 1 unmatched study^101^ trended toward decreased mortality with robot, and the remaining 2 unmatched studies demonstrated no difference between these approaches.^95,98^

Figure 10 Ventral Hernia Postoperative Short-term Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted ventral hernia repair and either laparoscopic (green) or open (gold) approaches. Studies utilizing propensity matching (circles) are listed in the left-hand side, while studies that did not utilize propensity matching (squares) are listed on the right-hand side.

Figure 11 presents the results for ventral hernia recurrence, the only postoperative long-term outcome for ventral hernia repair. Of the 7 studies included in this analysis,^89,91,93,95–97,106^ 5 studies compared robot-assisted surgery to the laparoscopic approach,^76,93,95–97^ while 2 studies^89,91^ compared the robot-assisted approach to the open approach. Only 1 matched study demonstrated a slight but significantly decreased recurrence rate following robot-assisted ventral hernia repair compared to laparoscopic repair,^96^ while the other matched study^97^ and 3 unmatched studies^76,95,97^ demonstrated a trend toward decreased hernia recurrence compared to laparoscopic repair without significance. The 2 studies comparing robot-assisted to open approaches revealed a non-significant trend toward increased recurrence rate.^89,91^

Figure 12 presents the results for postoperative pain following ventral hernia repair. Only 3 studies were included in this analysis,^96,101,102^ which all compared robot-assisted surgery to laparoscopic repair. The matched study demonstrated no difference between the approaches,^96^ while 1 unmatched study demonstrated a significant decrease in pain following robot-assisted ventral hernia repair,^102^ and the remaining unmatched study favored the robot-assisted approach without significance.^101^

Figure 11 Ventral Hernia Postoperative Long-term Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted ventral hernia repair and either laparoscopic (green) or open (gold) approaches. Studies utilizing matching (circles) are listed in the left-hand side, while studies that did not utilize matching (squares) are listed on the right-hand side.

Figure 12 Ventral Hernia Postoperative Pain Outcomes

Graphed is the point estimate and 95% confidence intervals for the difference in the indicated outcome between robot-assisted ventral hernia repair and laparoscopic (green) approaches. Studies utilizing matching (circles) are listed in the left-hand side, while studies that did not utilize matching (squares) are listed on the right-hand side.

### Summary of Findings

Operative room time was significantly longer in robot-assisted ventral hernia repair compared to both the laparoscopic and open approaches in all but 1 study included. There was no evidence of a difference in intraoperative complication rate among the 3 approaches. There is a possible trend toward decreased transfusion rate with robot-assisted surgery compared to laparoscopic and open repairs, with 1 matched study demonstrating a significant difference favoring robot-assisted surgery and another demonstrating no difference. With regard to conversion to open surgery, most studies demonstrate a decreased rate of conversion with robot-assisted surgery compared to the laparoscopic approach. Robot-assisted ventral hernia repair appears to have significantly decreased LOS compared to open repair; however, this decrease may be less significant when compared to laparoscopic repair. There is a likely decrease in postoperative complication rate following robot-assisted repair compared to both laparoscopic and open approaches based on the results of matched studies (unmatched studies do not support this trend). There may be a small signal favoring robot-assisted ventral hernia repair for reducing postoperative SSIs compared to open surgery; however, there does not appear to be evidence of a difference when compared to the laparoscopic approach. There is no evidence of a difference in readmission or mortality rates among the approaches. In terms of hernia recurrence, the 2 studies comparing robot-assisted ventral hernia repair to open surgery demonstrated no difference, while there may be a slight trend favoring robot-assisted ventral hernia repair compared to laparoscopic surgery based on results from 1 matched study. Finally, there may be a small signal of decreased postoperative pain favoring the robot-assisted approach when compared to the laparoscopic approach based on significant findings from 1 unmatched study. However, the matched study does not support this.

### Certainty of Evidence for Key Question 1C

All studies included in this analysis were observational studies, which decreased the overall certainty of evidence. The 1 available RCT was too limited in detail to use in our analysis. We judged the certainty of evidence for the outcome of increased OR time for robot-assisted ventral hernia repair compared to open and laparoscopic repairs as high due to the consistency among nearly all studies included in this analysis, except for 1 unmatched study. We judged the certainty of evidence that there is no difference in intraoperative complications among the approaches as low due to inconsistency and imprecision. We judged the certainty of evidence that there is the same or slightly decreased rate of transfusion for robot-assisted surgery compared to open and laparoscopic hernia repairs as low because the few matched studies that assessed this particular outcome were inconsistent and imprecise. We judged the certainty of evidence that there is a decreased conversion rate to open surgery with robot-assisted surgery compared to laparoscopic surgery as low, as the data was consistent but imprecise. We judged the certainty of evidence that robot-assisted ventral hernia repair decreased LOS compared to open surgery and less significantly when compared to laparoscopic surgery as moderate, based on preciseness and consistency across matched and unmatched studies. Both outcomes of postoperative complications and SSI were deemed to have low certainty of evidence due to the inconsistency and imprecision of the data. Mortality and readmissions were judged to be equivalent across the 3 approaches with moderate certainty of evidence. There is low certainty that there may be a minimal difference in hernia recurrence favoring robot-assisted ventral hernia repair compared to laparoscopy and no difference compared to open surgery. Finally, there is a low certainty that there is no difference in postoperative pain following ventral hernia repair in the 3 approaches, based on only 2 studies.

Table 5 Certainty of Evidence for Ventral Hernia Repair Studies

Outcome | Study Limitations | Consistency | Directness | Precision | Certainty of Evidence
Intra-operative
Operating Room Time; Robot >Open/Laparoscopy | Unmatched observational studies: High; Matched observational studies: Moderate | Consistent | Direct | Precise | High
Intraoperative Complications; Robot = Open/Laparoscopy | Unmatched observational studies: High; Matched observational studies: Moderate | Inconsistent | Direct | Imprecise | Low
Transfusion; Robot <Open/Laparoscopy | Matched observational studies: Moderate | Inconsistent | Direct | Imprecise | Low
Conversion to Open Surgery; Robot <Laparoscopy Robot >Open | Unmatched observational studies: High; Matched observational studies: Moderate | Consistent; Consistent | Direct; Direct | Imprecise; Imprecise | Low; Low
Postoperative Short-term
Length of Stay; Robot <Open/Laparoscopy | Unmatched observational studies: High; Matched observational studies: Moderate | Consistent | Direct | Precise | Moderate
Postoperative Complications; Robot <Open/Laparoscopy | Unmatched observational studies: High; Matched observational studies: Moderate | Inconsistent | Direct | Imprecise | Low
Surgical Site Infection; Robot <Open Robot = Laparoscopy | Unmatched observational studies: High; Matched observational studies: Moderate | Inconsistent; Inconsistent | Direct; Direct | Imprecise; Imprecise | Low; Low
Readmissions; Robot = Open/Laparoscopy | Unmatched observational studies: High; Matched observational studies: Moderate | Consistent | Direct | Imprecise | Moderate
Mortality; Robot = Open/Laparoscopy | Unmatched observational studies: High; Matched observational studies: Moderate | Consistent | Direct | Imprecise | Moderate
Postoperative Long-term
Hernia Recurrence; Robot = Open/Laparoscopy | Unmatched observational studies: High; Matched observational studies: Moderate | Consistent | Direct | Imprecise | Low
Pain
Pain; Robot <Laparoscopy | Unmatched observational studies: High; Matched observational studies: Moderate | Consistent | Direct | Imprecise | Low

## KEY QUESTION 2C VENTRAL HERNIA SURGERY: what is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for ventral hernia repair?

We identified 6 studies that compared robot-assisted ventral hernia to other approaches and provided some data on costs. Two were single institution studies,^103,107^ 2 used the National Inpatient Sample,^94,98^ 1 used the Vizient administrative database,^104^ and 1 used a surgical registry.^101^ One study reported only cost data and no clinical outcomes.^107^ All compared robot-assisted to laparoscopic surgery, with 2 also including an open comparison. Three studies found the robot approach to be more expensive than laparoscopic surgery, 1 found the robot-assisted approach had a non-statistically significant higher cost than laparoscopy, and 2 found the robot-assisted surgery and laparoscopy were similar with respect to costs.

As with inguinal hernia, the methodology of the included studies was very limited, especially as it relates to details regarding how costs were derived. Evidence of the diversity of methods used is the fact that cost estimates ranged from as low as $4,000 to as high as $61,000 for the cost of the robot. This reflects the fact that when measuring costs, investigators must be very specific about the perspective (cost vs charge), time frame (just OR, OR and hospital stay, hospital stay + 30/90 days), and explicit details about what is and is not included in cost estimates (direct vs indirect, variable vs fixed, etc). None of the studies included all of these details. Most studies provided less than 1 sentence about how cost estimates were derived. Several studies relied on administrative databases and used cost-to-charge ratios to estimate hospital costs. Previous research has demonstrated that these measures are prone to bias, especially in surgery.^11,108^ It is unlikely that these methods adequately capture the nuance of cost intrinsic to the robot, such as the amortization of the purchase price, the service contract, and the semi-variable cost of the surgical instruments. As with the inguinal hernia studies, none of these studies comment on staff costs nor did they follow reporting guidelines (eg, Second Panel on Cost Effectiveness, CHEERS). Two of the included studies did find the operative time was longer for the robot-assisted approach compared to the laparoscopic approach, with 1 study finding the operative times of robot-assisted cases were approximately double those of the laparoscopic cases (240 minutes versus 120 minutes). When dealing with large differences in time, consideration must be given to staffing costs and, perhaps more importantly, the opportunity cost of not performed cases.

Table 6 Evidence Table for Ventral Hernia Cost Studies

Author, Year, Number | Study Design, Number of Institutions | Comparison | Number of surgeons | Sample Size | Source of cost data | Cost data | Misc. outcomes
Armijo, 2018^104^ | Retrospective review of Vizient database | Robot-assisted vs laparoscopic vs open ventral hernia repair | Not stated | 39,505 open; 6,829 lap; 465 robotic | “Ratio of cost-to-charge method applied for estimating cost of patient care…” | Total direct cost: $9000 (open), $7000 (lap), $10,000 (robot) | Median LOS was 5 days (open), 3 days (lap), 2 days (robot)
Coakley, 2017^98^ | Retrospective review of National Inpatient Sample (2008-2013) | Robot-assisted vs laparoscopic ventral hernia repair | Not stated | 351 robotic; 32,243 lap | “Total hospital charges…” | Adjusted model (controlling for CCI, geographic, public vs private etc) mean charges were $41,911 (lap) vs $61,205 (robot) | LOS no different lap vs robot (3.4 days lap, 3.5 days robot, p=NS)
Khorgami, 2019^94^ | Retrospective review of National Inpatient Sample (2012-2014) | Robot-assisted vs laparoscopic ventral hernia repair | Not stated | 3600 lap; 99 robotic | “Hospital total charges were converted to cost estimates using hospital specific cost-to-charge ratios provided by HCUP. Admissions with total charges below 0.1 percentile or above 99.9 percentile were considered outliers and excluded from analysis.” | $10,739 (lap) vs $13,441 (robotic); p-value not provided | LOS 2.7 days (lap) vs 2.9 days (robot); p-value not provided
Song, 2017^103^ | Retrospective review, Premier Perspectives Database, Abstract only | Robot-assisted vs lap vs open elective ventral hernia repairs in patients with BMI >30 | Not stated | 2 samples (depending on comparison)… 94/94 robot vs lap and 96/96 robot vs open | “total cost included direct cost and overhead cost and was adjusted for inflation to 2015 US dollars” | All were the same. approximately $10,500 (p=NS) | OR time was 231 min (robot), 169 min (lap), and 163 min (open). robot and lap (<.0001); LOS was 3.1 days (robot), 3.2 days (lap), 5.3 days (open); robot vs open (p=0.003)
Tan, 2017^107^ | Retrospective review, single institution, Abstract only | Robot-assisted vs laparoscopic ventral hernia repairs | 1 | 46 robotic; 47 lap | Primary outcome: “disposable operating room costs”; Secondary outcomes: “technical direct costs such as costs from the laboratory or pharmacy…” | Median total variable costs were $4,551 (lap) versus $4362 (robot), p=NS; OR median costs were $3,391 (lap) versus $3,095 (robot), p=NS | Results state no difference in OR time or LOS but no data
Warren, 2017^101^ | Retrospective review, Americas Hernia Society Quality Collaborative (multi-institutional) | Robot-assisted vs laparoscopic ventral hernia repair | Not stated | 103 lap; 53 robotic | No details provided | Mean direct hospital cost $13,943 (lap) vs $19,532 (robotic), P=NS | Operative time 121 min (lap) vs 245 min (robotic), p<0.001

### Summary of Findings

There are only a handful of cases comparing the costs of robot-assisted versus laparoscopic or open surgery for ventral hernia repair. All had significant limitations, primarily surrounding the cost methodology used. However, 4 of the 6 studies reported that the robot-assisted approach was more expensive than either the laparoscopic or open approach (with large effect size) and the other 2 studies reported no difference in cost as compared to laparoscopic repair.

### Certainty of Evidence for Key Question 2C

We have low certainty that robot-assisted surgery is more expensive than laparoscopic ventral hernia repair or open ventral hernia repair based on inconsistency and imprecision (studies were all observational). We have insufficient data to render a statement regarding the cost of robot-assisted versus the other surgical approaches. Importantly, since there were no formal cost-effectiveness analyses, no conclusion can be made in this regard as well.