# METHODS

## TOPIC DEVELOPMENT

This topic was developed in response to a nomination by Dr. Mark Wilson, National Director of Surgery, and Dr. William Gunnar, former National Director of Surgery. Key questions were then developed with input from the topic nominator, the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

The Key Questions were:

KQ1A What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic surgery for cholecystectomy?
KQ2A What is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic surgery for cholecystectomy?
KQ1B What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for inguinal hernia repair?
KQ2B What is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for inguinal hernia repair?
KQ1C What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for ventral hernia repair?
KQ2C What is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for ventral hernia repair?

Because the 3 surgical procedures were different, we constructed separate search strategies, inclusion and exclusion criteria for each procedure.

The review was registered in PROSPERO and is awaiting registration number.

## SEARCH STRATEGY

We conducted separate searches for cholecystectomy, inguinal hernia, and ventral hernia. All searches included PubMed, Embase, and Cochrane (all databases) from 2010 to March 2020. For inguinal and ventral hernias, Medline was also searched from 2010 to 2020. The search used a broad set of common terms relating to “robotic surgical procedures” or “robotic-assisted” and “cost effectiveness”, and then the individual procedure-specific terms “inguinal hernia”, “ventral hernia” or “incisional hernia”, and “cholecystectomy”. Prior to 2010, robot-assisted procedures were not widely being performed and many surgeons were still in the so-called “learning curve”. As such, our technical expert panel considered evidence from studies published prior to the year 2010 to be insufficiently relevant to modern practice. While we still anticipated finding studies assessing or including the robot-assisted surgery learning curve, this later search date will help lessen that occurrence. See Appendix A for complete search strategy.

## STUDY SELECTION

Multiple team members working independently screened the titles of retrieved citations. For cholecystectomy, MMG and RS; for inguinal hernia repair, LY and MMG; for ventral hernia repair, LY, RS, MG, and MMG.

For titles deemed relevant by at least 1 person, abstracts were then screened independently in duplicate by multiple team members working in pairs. For cholecystectomy, RS and MMG; for inguinal hernia repair, LY, AT, and MMG; for ventral hernia repair, LY and MMG.

All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by 2 independent team members, with any disagreements resolved through discussion. For cholecystectomy, RS and MM; for inguinal hernia repair, LY and AT; for ventral hernia repair, LY and MMG.

Studies were included at either the abstract or the full-text level if they were randomized control trials or observational studies comparing robot-assisted surgery with either laparoscopic or open surgical approaches for any of the included surgical procedures. We also included publications of cost-effectiveness models that compared robot-assisted surgery with laparoscopic or open surgical approaches. We included all RCTs regardless of outcomes studied. We did not have sample size restrictions for cholecystectomy, but excluded studies with sample size <10 for inguinal and ventral hernia repairs. The cholecystectomy technique is very standard (with the exception of the number of ports). However, both hernia repair techniques are widely variable including factors such as mesh location, size of hernia, type of sutures, use of tacks, use of sutureless mesh, etcetera, and these continue to evolve. These factors were not consistently reported. As such, we made the decision that the small studies (<10 sample size) would have the potential for substantial unmeasured bias.

## DATA ABSTRACTION

Data extraction was completed in duplicate. All discrepancies were resolved with full group discussion. We abstracted data on the following: study design, patient characteristics, sample size, intraoperative outcomes, postoperative outcomes, long-term functional outcomes and cancer outcomes, duration of follow-up, and data needed for the Cochrane Risk of Bias tool or Cochrane Risk Of Bias In Non-randomized Studies – of Interventions (ROBINS-I).

## QUALITY ASSESSMENT

Randomized controlled trials were assessed for quality (risk of bias) with the Cochrane Risk of Bias tool.^9^ This tool requires an assessment of whether a study is at high or low (or unknown) risk of bias in 7 domains: random sequence generation, allocation concealment, blinding of participants and personnel, blinding of outcome assessment, incomplete outcome data, selective outcome reporting, and other (See Appendix C for tool; Appendix E for table). We used the Risk Of Bias In Non-randomized Studies – of Interventions (ROBINS-I) for observational studies.^10^ This tool requires an assessment of whether a study is at critical, serious, moderate, or low risk of bias (or no information) in 7 domains: confounding, selection bias, bias in measurement classification of interventions, bias due to deviations from intended interventions, bias due to missing data, bias in measurement of outcomes, and bias in selection of the reported result (see Appendix D for tool; Appendix F for table).

The review team operationalized the 7 domains in the following manner:

- Confounding factors
  - Low: if patients have similar baseline characteristics, OR if significantly different, are propensity matched
  - Serious: if baseline data is not explicitly stated
- Selection bias
  - Low: if consecutive series, OR if *likely* consecutive from a database study
- Bias in measurement classification of interventions & bias due to deviation from intended interventions
  - Low: by nature of the included studies
- Bias due to missing data
  - Studies with outcomes of 30 days or less were assumed to be 100% follow-up
  - Moderate if loss to follow-up is unclear; serious if follow-up is reported, but low
  - If studies exclude missing data in their study design then serious selection bias, but low for bias due to missing data
  - If studies report an n-value in postoperative/long-term outcome tables that is consistent with their original n-value then that implies 100% follow-up
  - Low: if no/minimal loss to follow-up
- Bias in measurement of outcomes
  - Split up outcomes by risk if there are differences
  - OR times: likely low risk due to retrospective nature of most of these studies
  - Pain: moderate risk due to patient subjectivity, lack of concealment, possible physician counseling, etc.
- Bias in selection of the reported result
  - Low: if authors report all available data, especially data with no significant differences
  - Depends on the purpose and intended outcomes of the study, and whether other similar studies report omitted outcomes

## DATA SYNTHESIS

Because the RCTs were too heterogeneous, we did not conduct a meta-analysis of trials. The observational studies were too clinically heterogeneous to support meta-analysis; hence, our synthesis is narrative.

We assessed robot-assisted and laparoscopic approach for cholecystectomy, as open cholecystectomy is typically performed for only cancer pathology. Therefore, robot-assisted cholecystectomy to open cholecystectomy is not clinically relevant. We assessed robot-assisted, laparoscopic, and open approaches for inguinal and ventral hernia repairs. Of note, cholecystectomy (for benign disease) and most inguinal hernias are performed as outpatient surgery.

Further, since there were limited RCTs, specific considerations for each of the 3 operations types were warranted, in order to account for a number of potential differences between study arms. Specifically, we needed to assess for within-study variations in patient factors and varying surgical techniques, which could confound effect differences in clinical outcomes. For example, if a robot-assisted surgery study arm had a higher number of bilateral hernias than the laparoscopic group, this in and of itself could potentially be responsible for longer operative times or higher rate of complications. Studies that performed matching (propensity matching) in our review accounted for a number of important variables but typically did not control for all relevant patient or technique factors (ie, extent of fascial closure, hernia size, etc).

Specifically, our research team made the following judgments to allow for the most optimal comparisons of the studies identified (which were mainly observational).

- For cholecystectomy, we present the data by grouping studies based on the number of surgical access ports used:
  ○ robot single-port compared to laparoscopic single port or robot multi-port compared to laparoscopic multi-port;
  ○ robot single-port compared to laparoscopic multi-port;
  ○ robot compared to laparoscopic for those with unknown number of ports (in terms of outcomes).
  We did not identify any study reporting robot multi-port to laparoscopic single-port.
- For inguinal hernia repair, we present the data by grouping studies where hernia laterality (unilateral or bilateral) was:
  ○ known and at least <25% between comparative arms, or outcomes reported by laterality;
  ○ laterality not known.
- For ventral hernia repair, we present the data by grouping studies that:
  ○ attempted matching on patient, hernia, or technique factors;
  ○ matching not performed.

## RATING THE BODY OF EVIDENCE

We used the criteria of the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group.^11^ GRADE assessing the certainty of the evidence based of the assessment of the following domains: risk of bias, imprecision, inconsistency, indirectness, and publication bias. This results in categories as follows:

- High: We are very confident that the true effect lies close to that of the estimate of the effect.
- Moderate: We are moderately confident in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
- Low: Our confidence in the effect estimate is limited. The true effect may be substantially different from the estimate of the effect.
- Very low/Insufficient: We have very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.

## PEER REVIEW

A draft version of the report was reviewed by technical experts and clinical leadership. Reviewer comments and our response are documented in Appendix B.